# Results

## Overview

Of 7014 unique citations, 336 underwent full-text review (Figure 3). We identified 67 eligible systematic reviews, which mainly addressed older adults and/or those with dementia. We found no eligible reviews for individuals with PTSD and/or TBI. We also searched for primary research studies for individuals with PTSD or TBI; after screening 126 citations and reviewing the full text of 7 articles, we identified no eligible primary studies on long-term NHP. We did not find any ongoing clinical trials or VA funded research studies that addressed long-term NHP for these populations. Therefore, we were unable to address any of the KQ for these groups.

There were 20 eligible reviews addressing risk factors for long-term NHP, and all focused on older adults and/or those with dementia. Four reviews examined frailty status^16–19^ and the remaining reviews included a wide variety of factors within each review.^20–35^ Approximately half of reviews were conducted within the past 5 years, and 15% were high quality (Appendix 5.1). We prioritized all high-quality reviews^16,18,22^ and 3 of the medium-quality reviews^19,27,29^ (to more broadly cover populations and risk factors) for evaluating associations between specific risk factors and long-term NHP.

Of 47 eligible reviews addressing interventions to prevent or delay long-term NHP, more evaluated case management (8 reviews),^36–43^ caregiver support (10 reviews),^44–53^ respite care and adult day clinics (9 reviews),^54–62^ or preventive home visits (6 reviews).^63–68^ Fewer examined home-based primary care (2 reviews),^69,70^ or physical activity interventions (2 reviews).^71,72^ The remaining 10 reviews^73–82^ were either very broad in scope (eg, all nonpharmacologic interventions for dementia) or the single review addressing that topic (eg, occupational therapy). A third of eligible reviews on interventions were high quality, and 40% were conducted within the past 5 years. We prioritized all 15 high-quality reviews,^38,40,41,45,51,54,59,61,65,70,73,75,77,80,83^ 4 medium-quality reviews,^67,71,72,74^ and one low-quality review (due to this being the only review on that topic)^82^ for abstraction of results on specific intervention effects. Most prioritized reviews (60%) limited eligible studies to randomized controlled trials (RCTs).

We abstracted results for specific risk factors and interventions from a total of 26 prioritized eligible reviews (6 for risk factors^16,18,19,22,27,29^ and 20 for interventions^38,40,41,43,45,51,54,59,61,65,67,70–75,77,80,82^). Characteristics of these reviews are provided in Table 1. Descriptions of these results are provided below.

Figure 3 Search, Selection, and Prioritization of Eligible Systematic Reviews

^a^2 reviews—any nonpharmacologic intervention for adults with dementia; 1—any intervention for falls prevention; 1—any intervention for patient or caregiver stress; 1—different settings for personal assistance; 1—in-home healthcare or personal assistance; 1—assistive technologies; 1—demonstration projects to integrate acute and long-term care in US and Europe; 1—occupational therapy; and 1—light therapy

Table 1 Characteristics of 26 Prioritized Systematic Reviews (SR)

| Total # SR^a^ | Recent^b^ | Quality of SR: | | SR including: | | | # Unique Studies Evaluating NHP^d^
| Total # SR^a^ | Recent^b^ | High | Medium | Only RCTs | Multiple Study Designs^c^ | US Studies | # Unique Studies Evaluating NHP^d^
[underlined: Risk Factors:]
Frailty Status | 3 | 2 | 2 | 1 | — | 2 | 2 | 8
Other Risk Factors | 3 | 2 | 1 | 2 | — | 3 | 3 | 98
[underlined: Interventions:]
Case Management | 4 | 2 | 4 | — | 2 | 1 | 3 | 28
Caregiver Support | 2 | 1 | 2 | — | 2 | — | 1 | 7
Respite Care & Day Clinics | 3 | 1 | 3 | — | 2 | 1 | 3 | 22
Preventive Home Visits | 2 | — | 1 | 1 | 1 | 1 | 2 | 32
Home-Based Primary Care | 1 | 1 | 1 | — | — | 1 | 1 | —
Physical Activity | 2 | 2 | — | 2 | 2 | — | 1 | —
Others^e^ | 6 | 3 | 4 | 1 | 3 | 3 | 4 | 11

NHP=long-term nursing home placement; RCTs=randomized controlled trials; US=United States

a Number of SR prioritized per category, based on better quality and most recent searches.

b Search conducted 2013 or later.

c Included RCTs and various observational study designs (eg, cohort with or without comparator).

d Within each category, total unique primary studies identified as reporting long-term NHP

e 1—interventions for falls prevention; 1—different settings for personal assistance; 1—assistive technologies; 1—demonstration projects to integrate acute and long-term care in US and Europe; 1—occupational therapy; and 1—light therapy. 1 SR (on demonstration projects) was low quality.

### For older adults and/or those with dementia, what are potentially modifiable risk factors that lead to long-term nursing home placement? (KQ 1)

Of 6 prioritized reviews on risk factors, 3 focused on frailty status^16,18,19^ and 3 examined a variety of other risk factors.^22,26,29^ In abstracting results, we grouped factors into categories from our conceptual model (see Figure 1 and Methods), except for frailty status which we describe separately below. In these results, we focus on factors which may be addressed by healthcare providers, health systems, and/or public policies, although some of these factors may not be truly amenable to improvement or change (eg, degree of cognitive impairment). Demographic characteristics were not considered modifiable. Results on associations between specific risk factors and long-term NHP are summarized in Table 2. Detailed characteristics and results from prioritized reviews are found in Appendix 5.2.

Table 2 Summary of Results from 6 Prioritized Reviews^a^ on Potentially Modifiable Risk Factors of Long-term Nursing Home Placement for Older Adults

Category of Risk Factor | Description | Risk for NHP | Comments on Associations
Frailty status | Frailty phenotype or frailty scores | ↑ | 2 reviews reported qualitative summaries^16,18^ and 1 review reported metaanalysis (OR/RR 1.67 [95% CI 1.47, 1.89])^19^
Needs for Care | Physical and/or cognitive impairments | ↑ | 2 reviews reported qualitative summaries—1 review focused on adults with dementia,^22^ 1 on older adults in general^26^
Needs for Care | Poor health status | ↔/↑ | 2 reviews reported qualitative summaries—1 review on adults with dementia found no association,^22^ but 1 review on older adults reported greater NHP with lower self-rated health status^26^
Needs for Care | More behavioral & psychological symptoms (of dementia) | ↑ | 1 review reported qualitative summary, stating more symptoms “significantly increased the risk of [NHP] in most but not all studies…”^22^
Needs for Care | More prescriptions | ↑ | 1 review reported qualitative summary, stating that “a high number of prescriptions…[were] strong predictors of NHP”^26^
Personal & Social | Low level of physical activity | ↑ | 1 review reported qualitative summary, stating that “low activity level …had a moderate predictive effect on NHP.”^26^
Personal & Social | Poor social network | ↑ | 1 review reported qualitative summary, stating moderate evidence showed greater risk for “those with a poor social network…”^26^
Personal & Social | More caregiver burden & distress | ↑ | 1 review reported qualitative summary, stating that “[i]ncreased caregiver burden…were significant predictors of [NHP] in most studies…”^22^
Personal & Social | Poor caregiver health | ↔/↑ | 1 review^22^ reported meta-analysis for caregiver depression (HR 1.00 [95% CI 0.97–1.03]) and qualitative summary of health status (“markers of worse caregiver health…were significant predictors…”)
Systems & Environment | | ? | 1 review^22^ found 1 study that “examined the effect of several characteristics of the American continuing care system…”

↑=increased risk; ↔=no meaningful difference or effect; ↓=lowered risk; ?=reviews identified none or only 1 study; ADL=activities of daily living; CI=confidence interval; HR=hazards ratio; NHP=long-term nursing home placement; OR= odds ratio; RR=relative risk ratio

a Prioritized based on highest quality and most recent search.

#### Frailty Status

Frailty has been mainly conceptualized as either a phenotype of decreased physiologic reserve (with concomitant vulnerability to health stressors)^76,77^ or an accumulation of age-related deficits in health and function (ie, medical conditions and impairments).^84^ Within our conceptual framework, frailty status is most analogous to a combination of risk factors within the needs category, although some features of the frailty phenotype (eg, slow gait speed) do not correspond directly to impairments or symptoms. We prioritized 2 high-quality^16,18^ reviews and 1 medium-quality review^19^ that examined associations between a variety of frailty measures and long-term NHP. All 3 reviews included studies that used a variety of scoring systems to operationalize and measure frailty, some of which applied the frailty phenotype, while others used the deficit-accumulation model. Overall, these reviews identified 8 unique studies evaluating the relationship between frailty and long-term NHP (Table 1).^84–91^

One high-quality umbrella review focused on validity of frailty assessment instruments for adults 60 years and older living in any setting, and examined predictive accuracy of frailty for adverse health outcomes, including institutionalization.^16^ This umbrella review identified 1 systematic review^86^ that evaluated diverse older adult populations, and found frailty indices (based on the deficit-accumulation model) to be “sufficiently accurate to predict increased risk of…hospitalization and institutionalization at 12 months…” The systematic review based its conclusions about long-term NHP on 3 observational cohort studies—1 from the Netherlands^86^ and 2 from Canada.^85,88^ All 3 primary studies used administrative data, sometimes in combination with interview or survey data.

One high-quality review^18^ and 1 medium-quality review^19^ examined frailty in community-dwelling adults 65 years and older; these reviews together included 6 studies that evaluated long-term NHP,^84,87–91^ one of which was also identified by the review discussed above.^88^ Of the 5 additional unique studies, 1 used US data,^90^ 3 used Canadian cohorts,^84,89,91^ and 1 used Italian data.^87^ Long-term NHP was reported by participants or family in 4 studies,^84,87,89,90^ and assessment was unclear in 1 study.^91^ Three studies used frailty indices that applied the deficit-accumulation model,^84,89,91^ 1 study used the frailty phenotype,^90^ and one study used 2 measures that applied deficit-accumulation and phenotype models, respectively.^87^ One review^18^ conducted a qualitative synthesis, stating that institutionalization was one of the “most common outcomes [associated with] frailty…” The other review^19^ performed a quantitative meta-analysis, showing that frailty was associated with an overall pooled hazard ratio (HR) or risk ratio (RR) of 1.65 (95% CI 1.48, 1.84) for institutionalization.

In summary, all 3 reviews addressed both frailty phenotype and deficit-accumulation frailty scores and included studies that used many different scoring systems to operationalize definitions of frailty. Overall, using a variety of measures, presence of frailty (or higher frailty scores) was associated with higher risk for long-term NHP.

#### Needs for Care

Three prioritized reviews (1 high-quality^22^ and 2 medium-quality^20,22^) examined a wide range of risk factors. The high-quality review examined factors contributing to long-term NHP for adults with dementia,^22^ while the other 2 reviews included studies on older adults in general.^27,29^ Together, these 3 reviews included 98 unique primary research studies (Table 1). Two reviews provided qualitative summaries of results for associations with specific measures of impairments, symptoms, and/or complexity of medical care,^22,27^ but the third review evaluated summary risk assessment tools (excluding frailty indices) that predicted risk for institutionalization.^29^ While these risk tools often included a range of factors in the needs category,^92–95^ there were no results on associations with individual risk factors.^29^

Both reviews that provided results on specific risk factors applied Andersen’s Behavioral Model of Health Services Use^9^ to identify and describe factors. The review on risk factors in dementia^22^ reported 14 studies showing increased long-term NHP associated with greater impairment in basic or instrumental activities of daily living (ADL/IADL).^96–109^ Additionally, this review included 2 studies which showed no association with general health status or medical comorbidities.^96,110^ Some included studies also showed that more behavioral and psychological symptoms were associated with more long-term NHP,^98,108,109,111–126^ but 3 studies did not find an association.^127–129^

The other review included studies on older adults and also reported consistent associations between more ADL/IADL and/or cognitive impairment and higher risk of long-term NHP.^27^ This review categorized overall results for individual factors into strong, moderate, weak, or inconclusive evidence, and highlighted the minimum and maximum associations for each factor from studies that authors rated as high quality. For example, review authors stated there was strong evidence for higher long-term NHP associated with greater IADL impairment and noted the range of hazards ratios (HR) as 1.05–2.50.^27^ Similarly, there was strong evidence for associations of long-term NHP with greater ADL (HR range 1.32–3.70, odds ratio [OR] range 1.30–1.78)^130–133^ and cognitive impairment (OR range 1.44–1.55, HR 1.67).^131,134,135^ Additional factors with strong evidence were lower general health status (OR range 1.48–1.67, HR 3.40)^130,134,136^ and higher number of prescriptions (HR range 1.04–1.67, OR 1.15).^131,136,137^ Association of long-term NHP with specific health conditions such as arthritis and respiratory diseases were rated by review authors as inconclusive.

In summary, the most consistent and substantial associations were reported for functional and/or cognitive impairments, for both those with dementia and the general population of older adults. For older adults in general, poor self-reported health status and higher number of prescribed medications were associated with higher long-term NHP, but for those with dementia, general health status was not associated with long-term NHP. For those with dementia, most studies also found that behavioral and psychological symptoms were associated with long-term NHP.

#### Personal & Social Factors

Two prioritized reviews^22,27^ provided results on specific personal and social factors, while the third review^29^ examined summary risk assessment instruments and did not report associations for individual factors. The high-quality review on adults with dementia^22^ reported a quantitative meta-analysis that showed no overall association between caregiver depression and long-term NHP (HR 1.00 [95% CI 0.97, 1.03], reportedly using data from 9 studies, but exact studies were not identified in review). In qualitative synthesis, this review also reported increased long-term NHP was associated with higher caregiver distress or burden (8 studies),^98,100,108,113,129,138–140^ lower life satisfaction (2 studies),^112,116^ or poor caregiver health (2 studies).^100,141^

The medium-quality review^27^ examined risk factors for older adults in general and provided qualitative summaries. The following factors were rated as having moderate evidence for association with increased long-term NHP: poor social network (HR range 1.18–1.27, OR range 1.11–1.18)^131,133,135,142^ and low physical activity (OR 1.97)^132^.

#### Systems & Environmental Factors

Prioritized reviews on risk factors collectively found only one study that examined association of long-term NHP with specific systems or environmental factors. This study evaluated adults with dementia, was conducted more than 20 years ago, and found inconsistent results for a variety of factors.^104^ Overall, there was a large gap in evidence on systems and environmental factors.

### What is the effectiveness of interventions for preventing or delaying long-term nursing home placement? (KQ 2 & 3)

Results from 20 prioritized reviews on interventions are summarized in Table 3 (for 13 reviews that included only RCTs^38,40,41,45,51,54,59,65,67,72,73,75,80^) and Table 4 (for remaining 7 reviews that included multiple study designs^43,61,70,71,74,77,82^). In general, interventions were evaluated for older adults and/or those with serious chronic medical conditions (eg, dementia); no interventions clearly demonstrated overall benefit across studies for delaying or preventing long-term NHP. Reviews reported some interventions had positive effects in a subset of included studies (ie, for case management, caregiver support, and preventive home visits). Reviews on several other interventions, including home-based primary care and physical activity programs, did not identify studies that examined effects on long-term NHP. Detailed results from prioritized reviews on interventions are described below and found in Appendix 5.3 (for long-term NHP) and Appendix 5.4 (for secondary outcomes, such as mortality and hospitalizations).

Table 3 Interventions to Delay or Prevent Long-term Nursing Home Placement (NHP)—Summary of Results from 13 Prioritized Reviews that Limited Inclusion to RCTs^a^

Interventions; (# prioritized SR, # unique RCTs^b^) | Effect on NHP | Comments
Case Management; (2, 22) | ↔ | 2 reviews reported quantitative meta-analyses for adults with dementia—1 review found inconsistent results across different follow-up intervals (reduction in NHP at 6 and 18 months, but not at 10–12 and 24 months)^40^; 1 review found no overall decrease in NHP (RR 0.94 [95% CI 0.85, 1.03]) or delay in timing (WMD 77.8 days [95% CI −70.5, 226.1])^41^
Caregiver Support; (2, 7) | ↔/↓ | 1 review^45,143^ reported qualitative summaries, stating interventions for caregivers of adults with dementia “did not consistently improve…institutionalization for patients with memory-related disorders” but also highlighted results from 2 studies that demonstrated delay in NHP
Caregiver Support; (2, 7) | ? | 1 review^51^ on cognitive reframing for caregivers of adults with dementia found no RCTs reporting NHP
Respite Care & Day Clinics; (2, 14) | ↔ | 1 review^54^ reported quantitative meta-analysis for adult day clinics and found no overall decrease in NHP (OR 0.84, 95% CI 0.58, 1.21) or when separated by type of comparator
Respite Care & Day Clinics; (2, 14) | ? | 1 review^59^ on all types of respite care identified 1 RCT which showed delay to combined outcome of NHP and death
Preventive Home Visits; (1, 13) | ↔/↓ | 1 review^67^ reported quantitative meta-analysis and found no effect overall (RR 0.91 [95% CI 0.76, 1.09]) but suggested more intensive interventions (>9 visits) may decrease NHP
Physical Activity (2, 0) | ? | 2 reviews^71,72^ on frail or pre-frail older adults found no RCTs reporting NHP
Other; (3, 9) | ↔ | 1 review^73^ on a variety of interventions for falls prevention, reported qualitative summaries that multifactorial programs and exercise-focused interventions showed inconsistent effects
Other; (3, 9) | ? | 1 review^75^ on light therapy for adults with dementia found no RCTs reporting NHP
Other; (3, 9) | ? | 1 review^80^ on assistive technologies for adults with dementia found no RCTs reporting NHP

↑=increased or accelerated NHP; ↔=no meaningful difference or effect; ↓=delayed or prevented NHP; ? = reviews identified none or only 1 study; CI=confidence interval; HR=hazards ratio; NHP=long-term nursing home placement; OR= odds ratio; RR=relative risk ratio; RCTs=randomized controlled trial; SR=systematic review

a Prioritized reviews based on highest quality and most recent search; these reviews explicitly allowed only RCTs as study design of included articles.

b Included RCTs that reported results on NHP

Table 4 Interventions to Delay or Prevent Long-term Nursing Home Placement (NHP)—Summary Results from 7 Prioritized Reviews Including Multiple Study Designs^a^

Interventions; (# prioritized SR) | Effect on NHP | Comments
Case Management (2) | ↔/↓ | 1 review^83^ reported qualitative summary for adults with dementia, stating that programs ≤ 2 years did not “confer clinically important delays in time to [NHP]” (moderate strength of evidence) but interventions for those with “in-home spouse caregivers and continue services for longer than 2 years” may be effective (low strength of evidence)
Case Management (2) | ↔ | 1 review^83^ reported qualitative summary for adults with frailty or multimorbidity, stating no effect on NHP (low strength of evidence)
Case Management (2) | ? | 1 review^38^ on “reablement” interventions for older adults found only 1 study reporting NHP
Respite Care & Day Clinics (1) | ↑ | 1 review^61^ reported quantitative meta-analysis of “quasi-experimental”^b^ studies and found increased NHP (OR 1.79 [95% CI 1.02, 3.12])
Respite Care & Day Clinics (1) | ↓ | 1 review^61^ reported qualitative summary of observational cohort studies, stating that these “found some support for the benefits of respite care…”^144–146^
Preventive Home Visits (1) | ↔ | 1 review^65^ reported quantitative meta-analysis and found no effect overall (RR 1.02 [95% CI 0.88, 1.18]) or by different follow-up intervals
Home-Based Primary Care (1) | ? | 1 review^70^ found no study reporting NHP
Other (3) | ? | 1 review^74^ on occupational therapy found only 1 study reporting NHP
Other (3) | ? | 1 review^77^ on different settings or models of personal assistance found no studies reporting NHP
Other (3) | ↓ | 1 review^82^ reported qualitative summary of demonstration projects to better integrate acute and long-term care, stating decreased NHP occurred in 2 projects

↑= increased or accelerated NHP; ↔=no meaningful difference or effect; ↓= delayed or prevented NHP; ? = reviews identified none or only 1 study; CI=confidence interval; NHP= long-term nursing home placement; OR= odds ratio; RCTs=randomized controlled trial; SR=systematic review

a Prioritized based on highest quality and most recent search, these reviews included randomized trials and observational studies

b Review authors defined these as observational studies with a comparison group as control

#### Case Management

Four prioritized high-quality reviews^38,40,41,43^ included 29 unique studies that evaluated the effects of case management on long-term NHP. Two reviews^40,41^ focused on adults with dementia, while the other 2 reviews^38,83^ addressed older adults with different characteristics, including multiple chronic health conditions. Reviews included a variety of case management interventions that differed on the number and types of components. Case managers had variable professional backgrounds (most commonly nursing), and employed different modalities and frequencies of patient contact. Some interventions described inclusion of comprehensive geriatric assessments among their components, while other interventions did not (though they may have included components with similar goals). Often, interventions had some element of caregiver counseling and support. Included studies had follow-up periods from 1 to more than 10 years.

The 2 reviews focusing on adults with dementia^40,41^ included only RCTs and collectively identified 22 unique trials that reported effects on long-term NHP. One review^40^ conducted meta-analyses using data from 9 trials,^147–155^ stratifying by follow-up interval. There were decreased odds of long-term NHP at 6 months (OR 0.82 [95% CI 0.69, 0.98]) and 18 months (OR 0.25 [95% CI 0.10, 0.60]), but not at 10–12 months (OR 0.95 [95% CI 0.83, 1.08]) or 24 months (OR 1.03 [95% CI 0.52, 2.03]). The other review^41^ pooled data from 16 studies,^96,147,151,152,156–167^ and reported “no statistically significant effect of dementia [case management] compared to usual care” (risk ratio [RR] 0.94 [95% CI 0.85, 1.03]). Additionally, this review evaluated time to long-term NHP by meta-analysis using data from 5 studies^96,156,161,162,167^ and also found no difference (weighted mean difference 77.98 days [95% CI −70.5, 226.1]).

One prioritized review on case management included observational studies in addition to RCTs.^43^ This review evaluated case management for older adults with different characteristics, finding 10 studies on adults with dementia^147,149–152,155,168–171^ and 2 focused on frailty or multimorbidity^172,173^ that reported effects on long-term NHP. For dementia, review authors concluded that there was moderate strength of evidence that programs lasting 2 years or less did not “confer clinically important delays in time to nursing home placement…” However, the review also stated that interventions for adults with dementia “who have in-home spouse caregivers and continue services for longer than 2 years” may be effective for delaying long-term NHP (low strength of evidence). For adults with frailty or multiple chronic health conditions, review authors reported low strength of evidence that case management did not decrease long-term NHP.

One review addressed reablement or restorative care for older adults, and included RCTs and observational studies.^38^ Review authors stated that reablement may not be distinct from other types of services delivered at home, and defined it as a high-intensity, time-limited intervention oriented towards optimizing function and reducing care in the future. Description of intervention elements showed substantial overlap with goals and components of case management. This review identified only one trial evaluating long-term NHP, which showed no differences.^174^

In summary, most evidence indicated that case management did not delay or reduce long-term NHP, with the possible exception of dementia programs lasting longer than 2 years and involving in-home spouses as caregivers.

#### Caregiver Support

Two high-quality prioritized reviews^45,51^ focused on caregiver support interventions, and both included only RCTs. One review^45^ was based on a VA ESP report^143^ that evaluated diverse interventions for caregivers of adults with dementia or cancer. Review authors reported qualitative summary of 7 studies that evaluated long-term NHP, all of which were for caregivers of those with dementia.^96,164,166,167,171,175,176^ Authors stated that caregiver involved interventions “did not consistently improve…institutionalization for patients with memory-related disorders,”^143^ but highlighted results from 2 studies that demonstrated delay in long-term NHP (228–557 days).^171,176^ Both of these studies evaluated the same model of caregiver support, which included tailored in-person counseling (6 sessions over the first 4 months), information and encouragement to attend local support groups, and ad hoc follow-up by counselors via different modalities.^171,176^

The other review^51^ addressed only cognitive reframing interventions for caregivers of adults with dementia. Although review authors intended to examine long-term NHP, they did not identify any studies that reported effects on this outcome.

In summary, evidence indicated that caregiver support interventions were generally not effective for preventing or delaying long-term NHP, although a few studies have reported benefits of a particular model of high-intensity caregiver counseling.

#### Respite Care & Adult Day Clinics

Three high-quality reviews examined respite care and/or adult day clinics, and collectively identified 22 unique studies. Two reviews limited inclusion to RCTs; one of these reviews focused on adult day clinics for a variety of populations,^54^ while the other examined respite care in any setting (eg, residential, at home, or at day clinics) for those with dementia.^59^ The first review^54^ included studies of adults with different medical conditions, and conducted quantitative meta-analysis using data from 13 RCTs.^177–189^ There was no overall benefit for decreasing institutionalization (pooled OR 0.84 [95% CI 0.58, 1.21]), or in subgroup analyses by different categories of comparators (eg, OR 0.91 for day clinic versus comprehensive geriatric care [95% CI 0.70, 1.19]). The other review (examining respite care for adults with dementia)^59^ included one RCT, but this trial used a combined outcome of days in the community, defined as not experiencing institutionalization or death.^190^ This trial showed more days in the community for the intervention group (22 days on average).^190^

The third review included both RCTs and observational studies of respite care in any setting for adults with a variety of conditions.^61^ This review included 8 studies on long-term NHP—1 RCT,^156^ 4 “quasi-experimental” studies (non-randomized prospective studies with any comparative control),^191–194^ and 3 observational cohort studies.^144–146^ The 1 trial compared caregiver training program with 10 days of respite care as the control; this showed shorter time to long-term NHP for the respite care group.^156^ Review authors conducted meta-analysis using data from 3 of the quasi-experimental studies,^191–193^ and found increased long-term NHP in the respite care groups (OR 1.79 [95% CI 1.02, 3.12] for long-term NHP, and OR 1.54 [95% CI 1.01–2.33] for combined long-term NHP or death). One quasi-experimental study^194^ was not included in the meta-analysis but review authors described that this showed “respite users tended to keep the care recipient in the community for significantly longer than matched control subjects.” Qualitative summary was provided for remaining 3 cohort studies^144–146^—“observational studies found some support for the benefits of respite care…” This review also included qualitative studies on how caregivers perceived use of respite care, and authors concluded “it is likely… that many samples recruited to studies of respite care are at a relatively late stage in the caregiving career and respite is unlikely to have a substantial impact on institutionalization rate.”

In summary, adult day clinics do not decrease long-term NHP but the evidence for respite care (in a variety of settings) is inconclusive, due to few RCTs and concerns about confounding factors in observational study designs.

#### Preventive Home Visits

Two prioritized reviews^65,67^ examined preventive home visits and, together, identified 32 unique studies which evaluated long-term NHP. In contrast to case management interventions, preventive home visits generally included older adults (eg, from population registries or general practitioner panels) who did not have known impairments, recent adverse health events, or high-risk diagnoses at the outset. Nearly all included studies employed health professionals (nurses, physicians, and/or social workers) as visitors; only 1 study used non-professional volunteers.^195^ The medium-quality review^67^ included only RCTs and conducted quantitative meta-analysis using data from 13 trials.^136,138,140–142,144,145,152,202,279,282–284^ This review found that overall “reduction in the risk of [long-term NHP] was modest and nonsignificant” (RR 0.91 [95% CI 0.76, 1.09]), but there was evidence of substantial heterogeneity. In subgroup analysis using data from 4 studies with more than 9 visits,^196–199^ authors reported “the estimated reduction [of long-term NHP]…was 34% (RR, 0.66; 95% CI, 0.48–0.92) and the typical risk difference was 2.3%.” Review authors excluded “short-term and residential or board and care-unit admissions” in abstracting results on long-term NHP.^67^

The other review^65^ was high quality and included both RCTs and studies using “quasi-random methods that approximated the characteristics of randomization” to allocate participants. The quantitative meta-analysis for institutionalization used data from 26 studies^108,136–143,146,149,151,201,266,268–279^ and showed no overall effect of home visits (RR 1.02 [95% CI 0.88, 1.18]). Review authors concluded there was “moderate quality evidence of no clinically important difference” between intervention and control groups in overall effect; there were also no effects in analyses by different follow-up intervals (eg, RR 0.96 [95% CI 0.69, 1.33] for 8 studies with at least 3 years of follow-up^197–204^).

In summary, most evidence indicated no decrease in long-term NHP, but a few studies with greater intensity of home visits showed some reduction.

#### Other Interventions

One prioritized high-quality review^70^ evaluated home-based primary care and sought to examine long-term NHP. This review included 19 studies but none of these reported long-term NHP. One observational study evaluated the proportion of participants with admissions to a skilled nursing facility before and after initiation of home-based primary care, but this study did not distinguish between short-term stays for rehabilitation and long-term NHP.^205^

Two prioritized reviews^71,72^ examined physical activity interventions that involved mostly or exclusively exercise programs. Both were medium quality and included only RCTs with community-dwelling older adults who were frail or pre-frail. Neither review identified any trials that reported long-term NHP.

One high-quality review^73^ examined any type of intervention to reduce falls in older adults and included 9 RCTs that evaluated long-term NHP. Review authors reported evidence of heterogeneity and provided qualitative summaries of results. Seven trials^206–212^ used multifactorial interventions, which varied in type of components and intensity of participant contacts, and showed inconsistent results for long-term NHP (RR range 0.43–3.07). Review authors cautioned “prevalence of institutionalization in the control groups varied substantially, from 0.6 to 20.1 percent” and wide confidence intervals reflected that long-term NHP were rare events. Two trials^213,214^ used exercise only and showed “no statistically significant effect on participants transitioning to institutionalized care…” Other included studies on vitamin D, environmental modification, medication management, and psychological interventions did not report effects on long-term NHP.

One medium-quality review^74^ addressed occupational therapy interventions for older adults and found only 1 RCT^215^ that reported effects on long-term NHP. Review authors did not provide results from this trial. We examined this study and found that it evaluated occupational therapy at home for older adults who were recently hospitalized for falls; there were no significant differences in self-reported long-term NHP at 1 year.^215^

One high-quality review^77^ focused on different models of delivering personal assistance to address ADL impairment for older adults. This review found 1 study that reported average number of days in the community (ie, not hospitalized or in a nursing home); no separate data for long-term NHP was provided.^216^

One high-quality review on light therapy^75^ and 1 high-quality review on assistive technologies^80^ both addressed adults with dementia and failed to identify any study reporting long-term NHP.

One low-quality review^82^ evaluated demonstration projects that aimed to change current policies and practice towards “comprehensive integration of acute and long-term care services, including financial mechanisms…” Included projects occurred after the US National Long-term Care Demonstration (Channeling).^187^ The review provided qualitative summaries of 7 demonstrations in US, Canada, UK, and Italy, and reported 2 of these projects evaluated rates of institutionalization.^172,217^ Both programs occurred in Europe and involved case managers who assessed participants, coordinated care, and promoted utilization of HCBS; in one program, case managers directly managed the budget for HCBS and institutional long-term care services for their panels.^217^ Both studies reported decreased institutionalization.^172,217^

In summary, evidence on long-term NHP was mostly not available for a wide range of interventions, and studies on interventions for falls prevention may have lacked sufficient follow-up and/or sample size to detect differences in long-term NHP.