# Methods

## Topic Development

### Conceptual Model and Analytic Framework

To guide scope refinement and protocol development, we first established our conceptual model of factors contributing to long-term NHP. We reviewed existing frameworks, including Andersen’s Behavioral Model of Health Services Use,^9,10,11^ Lawton’s Person-Environment Model,^12,13^ and the Vulnerable Populations Model,^14^ that have been applied and adapted in past research addressing long-term NHP for adults with substantial physical and cognitive impairments. We sought to integrate and adapt key components, with the ultimate goal of generating an organizing framework to help address questions posed by our VA partners. Our conceptual model (Figure 1) included 3 categories of factors that interact: 1) [underlined: needs for care] due to physical or cognitive impairment and consequences of medical illness; 2) [underlined: personal and social factors] that may be resources or barriers to meeting needs; and 3) [underlined: systems and environmental factors] including access and quality of healthcare and social services. Collectively, factors in these 3 categories determine whether adults may remain at home or seek a higher level of care in nursing homes or alternative settings with substantial supports (eg, group homes).

Figure 1 Conceptual Model for Long-term Nursing Home Placement

^a^ Due to mental health and physical health conditions

^b^ Includes outpatient and inpatient care

^c^ Includes skilled healthcare at home (eg, nursing, physical therapy) and non-health services (eg, home aides)

Our conceptual model highlighted some of the complexities in the study of factors leading to long-term NHP and interventions to avoid or delay this outcome. Multiple factors across several categories likely change over time and may interact dynamically. Complex interventions involving several components addressing multiple factors may be needed to delay or avoid long-term NHP; such interventions present substantial challenges in analysis and interpretation of effects, particularly regarding the importance of individual components. Finally, factors in the systems and environment category may have substantial effects on long-term NHP, but addressing these factors may well be beyond the scope of individual healthcare facilities or systems.

We applied our conceptual model to develop the analytic framework and guide formulation of key questions regarding risk factors and interventions seeking to delay or prevent long-term NHP (Figure 2). Our analytic framework shows that a number of factors outside of immediate needs for care may contribute to long-term NHP. Interventions may seek to change modifiable risk factors or substitute services (to address needs) in settings other than nursing homes. We were particularly interested in HCBS, but we included a broad range of interventions and alternative community settings for higher level of care. Finally, different characteristics of participants may affect the ability of interventions to delay long-term NHP.

Figure 2 Analytic Framework for Evidence Review of Risk Factors and Interventions to Prevent or Delay Long-term Nursing Home Placement

### Key Questions (KQ)

For adults with physical and/or cognitive impairments:

KQ1 What are the modifiable risk factors that lead to long-term NHP?
KQ2 What is the effectiveness of home and community-based interventions, and group homes or medical foster homes, for preventing or delaying long-term NHP?
KQ3 Which characteristics of adults with impairments moderate the effectiveness of home and community-based interventions, group homes or medical foster homes, in preventing or delaying long-term NHP?

## Search Strategy

We searched for systematic reviews in the following databases, from inception until September 2018: MEDLINE, Sociological Abstracts, PsycINFO, CINAHL, and Embase. The search terms included MeSH and free text for: nursing homes and long-term care placement, populations more likely to have impairments (eg, older adults) or of special interest to VA (ie, PTSD or TBI), eligible interventions, and systematic reviews (Appendix 1). We supplemented these results with additional searches of the Cochrane Database of Systematic Reviews, Joanna Briggs Institute Database, Agency for Healthcare Research and Quality Evidence-based Practice Center (AHRQ EPC) reports, and VA ESP reports through November 2018. We also sought references from our expert advisory panel.

We anticipated that there might be areas without eligible reviews and discussed preliminary results with our VA partners and expert advisory panel. Due to the lack of eligible reviews on long-term NHP for individuals with PTSD and/or TBI, we undertook additional searches of published primary research, and ongoing observational studies and clinical trials. We queried MEDLINE from inception until November 2018 using MeSH and free-text terms for outcomes and interventions, as noted above; we removed terms for systematic reviews and older adults. For ongoing studies, we searched VA Health Services Research & Development-funded studies (www.hsrd.research.va.gov/research) and www.clinicaltrials.gov using text terms for PTSD, TBI, and interventions of interest.

## Study Selection

After duplicates were removed, search results were uploaded into DistillerSR (DistillerSR, Evidence Partners, Ottawa, Canada). We screened titles and abstracts using prespecified inclusion/exclusion criteria (Appendix 2). Articles underwent full-text review if at least one reviewer deemed it eligible during abstract screening. Exclusion of articles at screening required agreement of 2 reviewers. At full-text review, 2 individuals separately determined inclusion/exclusion and then resolved any conflicts through discussion. When consensus could not be reached, disagreements were discussed with a third reviewer.

Eligible populations of interest included community-dwelling adults with existing physical or cognitive impairments, or those with high risk of developing impairments due to advanced age or existing medical conditions; no specific conditions were required or excluded. Eligible reviews addressing KQ1 could include any number or type of risk factors. Eligible reviews addressing KQ2–3 examined many different interventions, including case management and geriatric assessment, caregiver support, respite care, preventive home visits, home-based primary care, and alternative group settings for high-level care (Appendix 2). We created a preliminary list of interventions to guide searches but we allowed for new interventions to emerge during screening and selection.

Articles were included if review authors clearly intended to examine long-term NHP as an outcome of interest. We anticipated that certain reviews may not distinguish between short-term post-acute care rehabilitation in nursing homes and long-term NHP; thus, we required that eligible reviews reported intent to focus on long-term NHP (or used similar terms such as “institutionalization”) as outcomes of interest in review objectives and/or included results on long-term NHP. If a review examined “nursing home admissions” as the outcome and explicitly counted short-term stays for rehabilitation within its definition, then the review was excluded. Although we hoped that reviews would clearly state their definition of long-term NHP (or “institutionalization”) and how authors determined that included studies had measured the relevant outcome, we found that reviews rarely provided this information.

## Data Abstraction & Quality Assessment

We assessed the quality of all eligible reviews using criteria adapted from AMSTAR 2^15^ and rated overall quality as high, medium, or low (Appendix 3). In general, a high-quality review met all applicable criteria (ie, at least “partial Yes” for all questions). Two reviewers independently rated each eligible review, and consensus was reached through discussion.

All eligible reviews underwent data abstraction by 2 reviewers for: target population(s) of review; dates of search queries; number and characteristic of included primary studies (location, setting and study design); if and how reviews determined long-term NHP; and risk factor or intervention. For results on specific associations with or effects on long-term NHP, we focused on the highest quality and most recent eligible systematic reviews that covered the broadest range of risk factors and interventions. For example, out of all eligible reviews on case management, 4 were high quality and among these, 2 were conducted within the past 5 years (the other 2 were published in 2013); we prioritized all 4 high-quality reviews on case management for further data abstraction. Additional data abstraction included: pooled effects (or qualitative summaries) for risk factors or interventions; moderation of intervention effects by participant characteristics; datasets used and method of ascertainment for long-term NHP; quality ratings and strength of evidence (as determined by review authors); conceptual frameworks used by reviews; and total number of unique primary studies evaluating long-term NHP that were identified by all prioritized reviews for each intervention. Data abstraction was done by one reviewer and overread by a second reviewer.

## Data Synthesis

Given the heterogeneity in populations, risk factors and interventions, we undertook a qualitative synthesis of results. First we noted which risk factors or interventions were addressed by eligible reviews, and determined the available evidence for different risk factors and interventions. Then we summarized the specific results on associations with risk factors or effects of intervention from the prioritized subset of higher quality, more recent, eligible reviews.

## Peer Review

A draft version of this report was reviewed by 6 technical experts, as well as VA operational partners. Their comments and our responses are presented in Appendix 4.