# Introduction

In fiscal year 2015, the Department of Veterans Affairs (VA) spent $5.3 billion on institutional care, and $2.1 billion for non-institutional home and community-based services (HCBS), with total costs for long-term care services making up 13% of its overall budget.^1^ In fiscal year 2020, VA is projected to spend $9.8 billion overall on long-term care services for eligible Veterans.^2^ This growth in VA costs for long-term care services is expected to continue, due to increased numbers of Veteran enrollees who have a high degree of service-connected disabilities.^1^ At the same time, recent legislation (Caregivers and Veterans Omnibus Health Services Act of 2010^3^ and VA Maintaining Systems and Strengthening Integrated Outside Networks [MISSION] Act of 2018^4^) have established and expanded financial support and services for informal caregivers – that is, family or friends who provide unpaid care for Veterans with substantial impairments. While the initial program of caregiver benefits and services was limited to Veterans who served after September 11, 2001, the VA MISSION Act expanded eligibility to those from earlier eras of service. Among Veterans requiring assistance from informal caregivers, approximately one-fifth served after 9/11 and there are substantial differences between these individuals and Veterans who served before 9/11—more post-9/11 Veterans have mental health conditions and their caregivers are twice as likely to lack support networks.^5^

In 2017, the VA Secretary launched the Choose Home Initiative to enhance VA policies and practices for supporting Veterans and their informal caregivers, and to improve collaboration with non-VA community groups.^6,7^ The overall objective of this initiative is to increase support for Veterans with substantial impairments and help these individuals remain in community settings, if that is their preference. The Choose Home Initiative is led by the VA Veterans Experience Office and works with stakeholders and experts within and outside of VA, including the VA Office of Geriatrics and Extended Care, VA Caregiver Support Program, Administration for Community Living in the US Department of Health and Human Services, and the Elizabeth Dole Foundation. To help VA policymakers understand the effects of HCBS, particularly with respect to avoiding long-term nursing home placement (NHP), the VA ESP was asked to provide a review of the evidence on modifiable risk factors for and interventions that aimed to delay long-term NHP for community-dwelling adults with physical and/or cognitive impairments.

In collaboration with representatives from the Choose Home Initiative, VA Veterans Experience Office, Geriatrics and Extended Care, and Caregiver Support Program (hereafter referred to as “VA partners”), we developed the conceptual and analytic frameworks, and refined the scope for this evidence report. In addition to individuals who have existing disabilities, or are at high risk for developing impairments (due to older age and/or chronic medical conditions), our VA partners also requested evidence on risk factors and interventions for adults with posttraumatic stress disorder (PTSD) and/or traumatic brain injury (TBI), due to the higher prevalence of these conditions among Veterans with service-connected disabilities.^8^ To adequately address the broad scope of risk factors and interventions for these diverse populations, and to fulfill the goal of providing specific recommendations for VA policies, we undertook an umbrella review of systematic reviews. We present qualitative summaries of results from the highest quality and most recent reviews covering the broadest range of risk factors and interventions. We also describe implications for policy and gaps in evidence.