# APPENDIX 5 Evidence Tables

Appendix 5.1 Characteristics of All Eligible Systematic Reviews (SR)

Appendix 5.2 Detailed Results from Prioritized Eligible Systematic Reviews on Potentially Modifiable Risk Factors for Long-term Nursing Home Placement in Older Adults

Appendix 5.3 Detailed Results from Prioritized Eligible Systematic Reviews on Interventions to Prevent or Delay Long-term Nursing Home Placement

Appendix 5.4 Detailed Results on Secondary Outcomes from Prioritized Eligible Systematic Reviews on Interventions