# APPENDIX 3 Quality Assessment

## 3.1 Quality Assessment Criteria (Modified Amstar 2^15^)

## 3.2 Quality Assessment for All Eligible Systematic Reviews

Author, Year | Research Questions include components of PICO? | Protocol established prior to conduct of review? | Explained selection of included study designs? | Comprehensive search strategy used? | Dual review for inclusion? Dual review for data extraction? | Assessed quality? | Meta analyses: Appropriate statistical methods and investigation of publication bias? | Reported any potential conflicts of interest? | Overall Quality
Apostolo, 2017^16^ | Yes | Yes | Yes | Yes | Yes | Yes | NA | Yes | High
Beswick, 2010^36^ | Yes | No | Yes | Yes | No; Yes | Partial Yes | Yes | Yes | Medium
Black, 2004^20^ | Yes | No | No | Yes | No | No | No | No | Low
Bottcher, 2015^37^ | Yes | No | Yes | Yes | Yes; No | Yes | NA | No | Medium
Brown, 2015^54^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | High
Burridge, 2007^21^ | No | No | No | Yes | No | Yes | NA | No | Medium
Cepoiu-Martin, 2016^22^ | Yes | Partial Yes | Yes | Yes | Yes | Yes | Yes | Yes | High
Cochrane, 2016^38^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | High
Dickinson, 2017^44^ | Yes | No | No | Yes | Yes | Yes | NA | Yes | Medium
Du Preez, 2018^55^ | No | No | No | No | No | Yes | NA | Yes | Low
Elkan, 2001^63^ | Yes | No | Yes | Yes | No | Yes | Yes | Yes | Medium
Ellen, 2017^56^ | Yes | No | No | Partial Yes | No | No | NA | No | Medium
Fields, 2014^57^ | No | No | Yes | Yes | No | No | NA | Yes | Low
Flint, 1995^58^ | Yes | No | No | Yes | No | Yes | NA | No | Low
Forbes, 2014^75^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | High
Frazier, 2005^23^ | No | No | No | Yes | No | No | NA | No | Low
Frost, 2017^71^ | Yes | Yes | Yes | Yes | Yes; No | Yes | Yes | Yes | Medium
Gawel, 2012^24^ | Yes | No | Yes | Yes | Yes; No | Yes | NA | No | Medium
Gilhooly, 2016^81^ | Yes | No | Yes | Yes | Yes; No | Yes | NA | Yes | Medium
Gine-Garriga, 2018^72^ | Yes | No | Yes | Yes | Yes | Yes | Yes; No | Yes | Medium
Goy, 2010^52^ | Yes | Yes | Yes | Yes | No | Yes | NA | Yes | Medium
Griffin, 2015^45^ | Yes | Yes | Yes | Yes | Yes | Yes | NA | Yes | High
Guirguis-Blake, 2018^73^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | High
Hedrick, 1989^76^ | Yes | No | No | Yes | No | No | No | No | Low
Hickam, 2013^83^ | Yes | Yes | Yes | Yes | Yes | Yes | NA | Yes | High
Jensen, 2015^46^ | Yes | No | No | Yes | Yes | Yes | Yes | Yes | Medium
Johri, 2003^82^ | Yes | No | Yes | Yes | No | No | NA | No | Low
Kojima, 2018^17^ | Yes | No | Yes | Partial Yes | No | Yes | No; Yes | Yes | Low
Lee, 2014^59^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | High
Lehmann, 2018^25^ | Yes | No | No | Yes | Yes; No | Yes | Yes; No | Yes | Medium
Luppa, 2008^26^ | Yes | No | Yes | Yes | No | No | NA | No | Low
Luppa, 2009^28^ | Yes | No | Yes | Yes | No | No | NA | Yes | Low
Luppa, 2010^27^ | Yes | No | Yes | Yes | No | Partial Yes | NA | Yes | Medium
Markle-Reid, 2006^64^ | Yes | No | Yes | Yes | No | Yes | NA | Yes | Low
Mason, 2007^60^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes; No | Yes | High
Mayo-Wilson, 2014^65^ | Yes | No | Yes | Yes | Yes | Yes | Yes | Yes | High
Montgomery, 2008^77^ | Yes | Yes | Yes | Yes | Yes | Yes | NA | Yes | High
O’Caoimh, 2015^29^ | Yes | No | No | Yes | Yes | Yes | NA | Yes | Medium
Olazaran, 2010^78^ | Yes | No | Yes | Yes | Yes; No | Partial Yes | Yes; No | Yes | Medium
Palmer, 2014^30^ | Yes | No | Yes | Partial Yes | Yes | No | NA | No | Low
Pamoukdjian, 2015^31^ | Yes | No | No | No | No | No | NA | Yes | Low
Parker, 2008^53^ | Yes | No | Yes | Yes | Yes; No | Yes | Yes; No | No | Low
Pimouguet, 2010^39^ | Yes | No | Yes | Yes | No | Partial Yes | NA | No | Low
Pinquart, 2006^47^ | Yes | No | Yes | Partial Yes | Yes; No | Yes | Yes; No | Yes | Medium
Ploeg, 2005^66^ | Yes | No | Yes | Yes | Yes | Yes | Yes; No | Yes | Medium
Reilly, 2015^40^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | High
Rydwik, 2012^32^ | Yes | No | No | Partial Yes | No; Yes | Partial Yes | NA | Yes | Medium
Shaw, 2009^61^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | High
Smits, 2007^48^ | No | No | No | Partial Yes | Yes; No | Yes | NA | No | Low
Snowden, 2017^33^ | Yes | No | No | Partial Yes | No | Partial Yes | NA | Yes | Medium
Spijker, 2008^79^ | Yes | No | Yes | Yes | Yes; No | Yes | Yes; No | Yes | Medium
Stall, 2014^69^ | Yes | No | No | Yes | Yes; No | Yes | NA | Yes | Medium
Sternberg, 2011^18^ | Yes | Partial Yes | No | Yes | Yes | Partial Yes | NA | Yes | High
Steultjens, 2004^74^ | Yes | No | Yes | Partial Yes | Yes | Partial Yes | NA | No | Medium
Stuck, 2002^67^ | Yes | No | Yes | Yes | Yes | Partial Yes | Yes | Yes | Medium
Suchowersky, 2007^34^ | Yes | No | No | Yes | No | No | NA | Yes | Low
Tam-Tham, 2013^41^ | Yes | Partial Yes | Yes | Yes | Yes | Yes | Yes | Yes | High
Torti, 2004^35^ | No | No | No | No | No | No | NA | No | Low
Totten, 2016^70^ | Yes | Yes | Yes | Yes | Yes | Partial Yes | NA | Yes | High
Van der Roest, 2017^80^ | Yes | Yes | Yes | Yes | Yes; No | No | NA | Yes | High
van Haastregt, 2000^68^ | Yes | No | No | Yes | Yes | Yes | NA | Yes | Medium
Vandepitte, 2015^49^ | Yes | No | Yes | Partial Yes | No | Yes | NA | Yes | Low
Vandepitte, 2016^62^ | Yes | No | Yes | Yes | Yes; No | Yes | NA | Yes | Medium
Van’t Leven, 2013^50^ | Yes | No | No | Yes | Yes; No | Yes | NA | Yes | Medium
Vermeiren, 2016^19^ | Yes | Yes | Yes | Partial Yes | Yes | Yes | Yes; No | No | Medium
Vernooij-Dassen, 2011^51^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | High
You, 2013^42^ | Yes | No | Yes | Yes | No | Yes | NA | Yes | Medium