# APPENDIX 2 Study Selection Criteria

| Inclusion | Exclusion
Participants | Adults with physical or cognitive impairment (or at high risk for developing new impairments) due to: older age, frailty, dementia, other chronic conditions, PTSD, and/or TBI | Adults dependent on medical technology (eg, ventilator); adults with no impairments and having little or very remote risk for new impairments
Interventions | Home-based primary care, outpatient geriatric assessment and case management; Outpatient or home-based rehabilitation, nursing services, or other medical care; Physical activity or exercise (not as part of rehabilitation program); In-home assistance with non-healthcare activities (home aides, home repair, etc); Caregiver interventions; Respite care; Adult day clinics; Community health workers, friendly visits; Nutritional programs (Meals on Wheels, congregant dining, grocery delivery, etc); Transportation and mobility services; Assistive technologies; Alternative housing with range of services (assisted living or group homes, medical foster homes, etc); Financial support and benefits (eg, caregiver stipends, Cash and Counseling) | Hospice and end-of-life care; Condition-specific medications (eg, donepezil for dementia)
Comparators | Any (active or inactive)
Outcomes | Primary: Long-term nursing home placement, (must specify as long-term or otherwise use term that indicates long-term placement eg, institutionalization); Secondary:; Function, quality of life; Hospitalizations; Resource use, costs, spend-down; Mortality; Harms (falls, medication errors) | Short-term admission to nursing homes for post-acute care; Caregiver outcomes without patient outcomes
Timing | Any duration
Setting | Community | Acute care settings (ie, emergency rooms and inpatient wards); Institutional settings (eg, skilled nursing facilities for rehabilitation)
Design | Systematic review: must have search strategy, eligibility criteria, and analysis/synthesis plan; may include randomized controlled trials, observational studies, and/or qualitative studies
Other | English Language