# APPENDIX 1 Search Strategies

## Ovid Medline Search for Systematic Reviews

1 | (meta-analy$ or metaanaly$ or meta analy$).tw. or exp Meta-Analysis/ or (systematic adj (review$ or overview$)).tw. or (systematic review or literature review or rapid review or umbrella review or meta synthesis or metasynthesis or meta-analysis or meta-synthesis or integrative review or data synthesis or comparative effectiveness review).mp.
2 | (case report or case series).tw.
3 | 1 not 2
4 | (((nursing home$ or care home$ or long-term care or institution$ or facility) adj5 (place$ or entry or admit$ or admission$)) or institutionalization).tw. or exp Homes for the Aged/ or Nursing Homes/ or Long-Term Care/
5 | 3 and 4
6 | aged.mp. or exp AGED/ or (elder$ or old age or ag?ing or advanced age or aged-related or late$ life or senior$ or geriatr$ or retired or frail elder$).tw. or ((old or older) adj (adult$ or people or person$ or male$ or female$ or m?n or wom?n or population$ or citizen$)).tw. or exp dementia/ or (dementia or Alzheimer$ or lewy body or pick$ disease or (frontotemporal adj2 degeneration) or (vascular adj2 dementia)).tw. or ((memory adj2 (problem$ or disorder$)) or cognition or cognitive disorders).tw.
7 | (TBI or mTBI or traumatic brain injur$).tw. or exp Brain Injuries, Traumatic/ or exp Stress Disorders, Traumatic/ or (((post-traumatic or posttraumatic or post traumatic) adj2 stress) or PTSD).tw.
8 | (Disabled or disabilit$ or impair$ or function$).tw.
9 | (6 or 7) and 8
10 | exp Health Services for the Aged/ or exp Community Health Services/ or exp Community Health Workers/ or exp Home Care Services/ or Home Health Aides/
11 | exp Geriatric Assessment/ or (geriatric$ adj5 assess$).tw.
12 | exp House Calls/ or (house adj5 call$).tw. or (home adj5 (intervention$ or visit$ or assessment$ or service$ or therapy or healthcare or health care or primary care or aides or nurs$ or visit$)).tw. or home-based.tw. or health visitor$.tw.
13 | exp Occupational Therapy/ or (occupation$ adj5 therap$).tw.
14 | exp Physical Therapy Specialty/ or (phys$ adj5 therap$).tw.
15 | exp Social Support/ or (social adj5 (support or intervention)).tw. or (psychosocial adj5 care).tw. or exp Social Isolation/ or exp Social Facilitation/
16 | exp Social Work/ or (social adj5 (program$ or work$)).tw.
17 | ((physical$ adj5 (exercise or fitness or activit$)) or (exercise adj5 (program$ or behavi$))).tw. or exp Exercise Therapy/ or exp Physical Fitness/ or exp WALKING/ or exp exercise movement techniques/ or tai chi.tw.
18 | exp Caregivers/ or exp FAMILY/ or exp FAMILY NURSING/ or (caregiver$ or carer$ or care giver$ or informal care$ or (family adj2 (care$ or therapy))).tw.
19 | exp Home Nursing/ or exp Night Care/ or (night$ adj2 care).tw. or exp Respite Care/ or (respite or day care or day clinic$).tw. or exp Day Care, Medical/
20 | exp Food Services/ or ((meals adj2 wheels) or congregant dining or grocery delivery).tw.
21 | exp Foster Home Care/ or medical foster home$.tw.
22 | exp Assisted Living Facilities/ or Group Homes/ or assisted living.tw.
23 | ((cash and counseling) or self-directed or consumer-directed).tw.
24 | (transport$ or mobili$).tw.
25 | or/10–24
26 | 3 and 9 and 25
25 | 5 or 26
26 | Limit to English

## Ovid Embase Search for Systematic Reviews

1 | (meta-analy$ or metaanaly$ or meta analy$).tw. or exp Meta-Analysis/ or (systematic adj (review$ or overview$)).tw. or (systematic review or literature review or rapid review or umbrella review or meta synthesis or metasynthesis or meta-analysis or meta-synthesis or integrative review or data synthesis or comparative effectiveness review).tw.
2 | (case report or case series or case study).mp.
3 | 1 not 2
4 | (((nursing home$ or care home$ or long-term care or institution$ or facility) adj5 (place$ or entry or admit$ or admission$)) or institutionalization).tw. or exp Home for the Aged/ or Nursing Home/
5 | 3 and 4
6 | (elder$ or old age or ag?ing or advanced age or aged-related or late$ life or senior$ or geriatr$ or retired or frail elder$).tw. or ((old or older) adj (adult$ or people or person$ or male$ or female$ or m?n or wom?n or population$ or citizen$)).tw. or exp dementia/ or (dementia or Alzheimer$ or lewy body or pick$ disease or (frontotemporal adj2 degeneration) or (vascular adj2 dementia)).tw. or ((memory adj2 (problem$ or disorder$)) or cognition or cognitive disorders).tw.
7 | (TBI or mTBI or traumatic brain injur$).tw. or exp Brain Injuries, Traumatic/ or exp Stress Disorders, Traumatic/ or (((post-traumatic or posttraumatic or post traumatic) adj2 stress) or PTSD).tw.
8 | (Disabled or disabilit$ or impair$ or function$).tw.
9 | (6 or 7) and 8
10 | exp Geriatric Assessment/ or (geriatric$ adj5 assess$).tw. or exp Health Services for the Aged/ or exp Community Health Services/ or exp Community Health Workers/
11 | exp home visit/ or exp home care/ or (house adj5 call$).tw. or (home adj5 (intervention$ or visit$ or assessment$ or service$ or therapy or healthcare or health care or primary care or aides or nurs$ or visit$)).tw. or home-based.tw. or health visitor$.tw.
12 | exp Occupational Therapy/ or (occupation$ adj5 therap$).tw. or exp Physical Therapy/ or (phys$ adj5 therap$).tw.
13 | exp Social Support/ or (social adj5 (support or intervention)).tw. or (psychosocial adj5 care).tw. or exp Social Isolation/ or exp Social Work/ or (social adj5 (program$ or work$)).tw.
14 | ((physical$ adj5 (exercise or fitness or activit$)) or (exercise adj5 (program$ or behavi$))).tw. or exp kinesiotherapy/ or exp Fitness/ or exp WALKING/ or tai chi.tw.
15 | exp Caregiver/ or exp FAMILY NURSING/ or (caregiver$ or carer$ or care giver$ or informal care$ or (family adj2 (care$ or therapy))).tw. or (night$ adj2 care).tw.
16 | exp Respite Care/ or exp Day Care/ or (respite or day care or day clinic$).tw.
17 | exp catering service/ or ((meals adj2 wheels) or congregant dining or grocery delivery).tw.
18 | medical foster home$.tw. or exp Assisted Living Facilities/ or assisted living.tw. or exp residential home/
19 | ((cash and counseling) or self-directed or consumer-directed).tw.
20 | (transport$ or mobili$).tw.
21 | or/10–20
22 | 3 and 9 and 21
23 | 5 or 22
24 | Limit 23 to English language

## Psycinfo Search for Systematic Reviews

1 | (meta-analy$ or metaanaly$ or meta analy$).tw. or exp Meta-Analysis/ or (systematic adj (review$ or overview$)).tw. or (literature review or rapid review or umbrella review or meta synthesis or metasynthesis or meta-synthesis or integrative review or data synthesis or comparative effectiveness review).mp.
2 | (((nursing home$ or care home$ or long-term care or institution$ or facility) adj5 (institutionalization or place$ or entry or admit$ or admission$)) or institutionalization).tw. or Nursing Homes/ or Long-Term Care/
3 | 1 and 2
4 | (TBI or mTBI or traumatic brain injur$).tw. or exp Traumatic Brain Injury/ or exp Posttraumatic Stress Disorder/ or (((post-traumatic or posttraumatic or post traumatic) adj2 stress) or PTSD).tw.
5 | (Disabled or disabilit$ or impair$ or function$).tw.
6 | 1 and 4 and 5
7 | 2 and 6
8 | exp Elder Care/ or exp Community Services/ or exp Home Care/ or exp Home Care Personnel/ or (community health service$ or community health worker$ or home care service$ or home health aide$).tw.
9 | exp Home Visiting Programs/ or (house adj5 call$).tw. or (home adj5 (intervention$ or visit$ or assessment$ or service$ or therapy or healthcare or health care or primary care or aides or nurs$ or visit$)).tw. or home-based.tw. or health visitor$.tw.
10 | exp Occupational Therapy/ or (occupation$ adj5 therap$).tw.
11 | exp Social Support/ or (social adj5 (support or intervention)).tw. or (psychosocial adj5 care).tw. or exp Social Isolation/ or exp Social Facilitation/
12 | exp Social Casework/ or (social adj5 (program$ or work$)).tw.
13 | ((physical$ adj5 (exercise or fitness or activit$)) or (exercise adj5 (therap$ or program$ or behavi$))).tw. or exp Physical Activity/ or exp Exercise/ or exp Physical Fitness/ or exp WALKING/ or tai chi.tw.
14 | exp Caregivers/ or exp FAMILY/ or (caregiver$ or carer$ or care giver$ or informal care$ or (family adj2 (nurs$ or care$ or therapy))).tw.
15 | ((home adj2 nursing) or (night$ adj2 care)).tw. or exp Respite Care/ or (respite or day care or day clinic$).tw. or exp Adult Day Care/ or exp Day Care Centers/
16 | (food service$ or (meals adj2 wheels) or congregant dining or grocery delivery).tw.
17 | exp Assisted Living/ or exp Group Homes/ or exp Independent Living Programs/ or assisted living.tw.
18 | ((foster adj2 care) or medical foster home).tw.
19 | ((cash and counseling) or self-directed or consumer-directed).tw.
20 | (transport$ or mobili$).tw.
21 | exp Geriatric Assessment/ or (geriatric$ adj5 assess$).tw.
22 | exp Physical Therapy/ or (phys$ adj5 therap$).tw.
23 | or/8–22
24 | aged.mp. or exp Aging/ or exp Geriatric Patients/ or (elder$ or old age or ag?ing or advanced age or aged-related or late$ life senior$ or geriatr$ or retired or frail elder$).tw. or ((old or older) adj (adult$ or people or person$ or male$ or female$ or m?n or wom?n or population$ or citizen$)).tw. or exp dementia/ or exp Alzheimer’s Disease/ or (dementia or Alzheimer$ or lewy body or pick$ disease or (frontotemporal adj2 degeneration) or (vascular adj2 dementia)).tw. or exp Membory Disorders/ or exp Cognitive Impairment/ or ((memory adj2 (problem$ or disorder$)) or cognition or cognitive disorders).tw.
25 | 6 and 23
26 | 1 and 5 and 23 and 24
27 | 2 and 26
28 | 1 and (2 or ((4 or 24) and 5 and 23))
29 | limit 28 to english language

## Sociological Abstracts Search for Systematic Reviews

S2 | noft(meta-analy* OR metaanaly* OR meta analy*) OR MAINSUBJECT.EXACT.EXPLODE(“Literature Reviews”) OR noft((systematic review* OR systematic overview* OR literature review OR rapid review OR umbrella review OR meta synthesis OR metasynthesis OR meta-synthesis OR integrative review OR data synthesis OR comparative effectiveness review))
S3 | MAINSUBJECT.EXACT(“Nursing Homes”) OR MAINSUBJECT.EXACT(“Long Term Care”) OR noft(nursing home place* or nursing home entry or nursing home admit* or nursing home admission* or care home place* or care home entry or care home admit* or care home admission* or long?term care place* or long?term care entry or long?term care admit* or long?term care admission* or facility place* or facility entry or facility admit* or facility admission* or institutionalization)
S4 | S2 AND S3
S5 | noft(TBI or mTBI or traumatic brain injur* or post-traumatic stress or posttraumatic stress or post traumatic stress or PTSD)
S6 | noft(disabled or disabilit$ or impair$ or function*)
S7 | S2 and S5 and S6
S8 | S3 and S7
S10 | Exact(“home health care” OR “health care services”) OR noft(community health service* or community health worker* or home health aid*)
S11 | noft(house call* or home intervention* or home visit* or home assessment* or home service* or home therapy or home healthcare or home health care or home primary care or home aid* or home nurse* or home visit* or home-based or health visitor*)
S12 | noft(occupation* NEAR/5 therap*)
S13 | noft(social support or social intervention* or psychosocial care or social isolation or social facilitation) OR Exact(“social support” OR “social services” or “social welfare”)
S14 | Exact(“social work”) OR noft(social program* or social work*)
S16 | Exact(“physical fitness”) OR noft(physical* exercise OR physical* fit* OR physical* activit* OR exercise program* OR exercise behavi* OR exercise therapy OR walking OR exercise movement OR tai chi)
S17 | Exact(“caregivers”) OR (family or caregiver* or carer* or care giver* or informal care* or family care* or family therapy or family nursing)
S18 | Exact(“home care” OR “respite care” OR “adult care services”) OR noft(home nursing or night* care or respite or day care or day clinic*)
S19 | noft(food service* or meals NEAR/2 wheels or congregant dining or grocery delivery)
S20 | Exact(“foster home care”) OR noft(medical foster home*)
S21 | Exact(“group homes” OR “assisted living” OR “assisted living facilities”) OR noft(assisted living)
S22 | Exact(“group homes” OR “coresidence” OR “assisted living” OR “assisted living facilities”) OR noft(assisted living)
S23 | noft(“cash and counseling” or self-directed or consumer-directed)
S24 | noft(transport* or mobili*)
S25 | Exact(“geriatric assessment”) OR noft(geriatric* NEAR/5 assess*)
S26 | noft(phys* NEAR/5 therap*)
S28 | S10 OR S11 OR S12 OR S13 OR S14 OR S16 OR S17 OR S18 OR S19 OR S20 OR S21 OR S22 OR S23 OR S24 OR S25 OR S26
S29 | Exact(“geriatric/geriatrics (see also aging, aged)” OR “alzheimer’s disease” OR “dementia disorders” OR “aged (see also aging, geriatric)” OR “dementia, vascular” OR “alzheimers disease” OR “dementia” OR “aging (see also aged, geriatric)”) OR noft(aged or elder* or old age* or ag?ing or advanced age or aged-related or late* life or senior* or geriatr* or retired or frail elder*) OR noft(old* NEAR/2 adult* or people or person* or male* or female* or m?n or wom?n or population* or citizen*) OR noft(dementia or Alzheimer* or lewy body or pick* disease or frontotemporal degeneration or vascular dementia or memory problem* or memory disorder* or cognition or cognitive disorder*)
S30 | S7 AND S28
S31 | S2 AND S6 AND S28 AND S29
S32 | S31 AND S3
S33 | S2 AND (S3 OR ((S5 OR S29) AND S6 and S28))

## Searches of Cochrane Database of Systematic Reviews, Joanna Briggs Institute (JBI) Evidence-Based Practice Database, VA Evidence Synthesis Program (ESP), and AHRQ Evidence-Based Practice Center (EPC)

Target Interventions | Search Terms (keywords in title/abstract)
Home-based primary care, outpatient geriatric assessment and case management | Home-based primary care; Geriatric Assessment; Home visits; House calls; Case management older adults; Case management PTSD; Case management TBI
Outpatient or home-based rehabilitation, nursing services, or other medical care | Home nursing; Home physical therapy; Home occupational therapy
Physical activity or exercise (not as part of rehabilitation program) | Physical activity program older adults; Physical activity program PTSD; Physical activity program TBI; Exercise program older adults; Exercise program PTSD; Exercise program TBI
In-home assistance with nonhealthcare activities (home aides, home repair, etc.) | Home health aide; Home repair
Caregiver interventions | Caregiver; (Edited to “caregiver adj3 intervention” in JBI)
Respite care | Respite care; (Edited to “respite adj2 care” in JBI)
Community health workers, friendly visits | Friendly visit/visitor
Nutritional programs (Meals on Wheels, congregant dining, grocery delivery, etc.) | Meals on Wheels; Congregant dining; Grocery delivery
Transportation and mobility services | Transportation; Mobility services
Assistive technologies | Assistive technology; (“home” and “community” added to search in Cochrane)
Alternative housing with range of services (assisted living or group homes, medical foster homes, etc.) | Assisted living; Group home; Medical foster home
Financial support and benefits (caregiver stipends, Cash and Counseling, etc.) | Caregiver benefits; Caregiver stipends; Cash and Counseling

## Ovid Medline for Primary Studies on TBI/PTSD Population

1 | (((nursing home$ or care home$ or long-term care or institution$ or facility) adj5 (place$ or entry or admit$ or admission$)) or institutionalization).tw. or exp Homes for the Aged/ or Nursing Homes/ or Long-Term Care/
2 | (TBI or mTBI or traumatic brain injur$).tw. or exp Brain Injuries, Traumatic/ or exp Stress Disorders, Traumatic/ or (((post-traumatic or posttraumatic or post traumatic) adj2 stress) or PTSD).tw.
3 | 1 and 2
4 | limit 3 to “all child (0 to 18 years)”
5 | 3 not 4
6 | limit 5 to english language