# REFERENCES

1 Institute of Medicine Committee on Quality of Health Care in A. Crossing the Quality Chasm: A New Health System for the 21st Century. Washington (DC): National Academies Press (US) Copyright 2001 by the National Academy of Sciences. All rights reserved.; 2001.
2 Elayan RM, Ahmad MM. Assessment of the Quality of Nursing Care From Perspectives of Nurses Who Experienced Hospitalization as Patients. J Nurs Care Qual. 2017;32(4):369–374.28448300
3 McHugh MD, Stimpfel AW. Nurse reported quality of care: a measure of hospital quality. Res Nurs Health. 2012;35(6):566–75.22911102
4 Aiken LH, Sermeus W, Van den Heede K, . Patient safety, satisfaction, and quality of hospital care: cross sectional surveys of nurses and patients in 12 countries in Europe and the United States. Bmj. 2012;344:e1717.22434089
5 Workforce SotUSHC. National Center for Health Workforce Analysis. 2024.
6 Stalpers D, Kieft R, van der Linden D, . Concordance between nurse-reported quality of care and quality of care as publicly reported by nurse-sensitive indicators. BMC Health Serv Res. 2016;16:120.27052745
7 Kutney-Lee A, Lake ET, Aiken LH. Development of the Hospital Nurse Surveillance Capacity Profile. Res Nurs Health. 2009;32(2):217–28.19161172
8 Smeds Alenius L, Tishelman C, Runesdotter S, . Staffing and resource adequacy strongly related to RNs’ assessment of patient safety: a national study of RNs working in acute-care hospitals in Sweden. BMJ quality & safety. 2014;23(3):242–9.
9 Poghosyan L, Clarke SP, Finlayson M, . Nurse burnout and quality of care: cross-national investigation in six countries. Res Nurs Health. 2010;33(4):288–98.20645421
10 Rafferty AM, Clarke SP, Coles J, . Outcomes of variation in hospital nurse staffing in English hospitals: cross-sectional analysis of survey data and discharge records. Int J Nurs Stud. 2007;44(2):175–82.17064706
11 Cho SH, June KJ, Kim YM, . Nurse staffing, quality of nursing care and nurse job outcomes in intensive care units. J Clin Nurs. 2009;18(12):1729–37.19646118
12 Smeds-Alenius L, Tishelman C, Lindqvist R, . RN assessments of excellent quality of care and patient safety are associated with significantly lower odds of 30-day inpatient mortality: A national cross-sectional study of acute-care hospitals. Int J Nurs Stud. 2016;61:117–24.27348357
13 Gurses AP, Carayon P, Wall M. Impact of performance obstacles on intensive care nurses’ workload, perceived quality and safety of care, and quality of working life. Health Serv Res. 2009;44(2 Pt 1):422–43.19207589
14 Patrician PA, Campbell CM, Javed M, . Quality and Safety in Nursing: Recommendations From a Systematic Review. J Healthc Qual. 2024;46(4):203–219.38717788
15 Moos RH, Schaefer JA. Evaluating health care work settings: A holistic conceptual framework. Psychology & Health. 1987;1(2):97–122.
16 Schalk DM, Bijl ML, Halfens RJ, . Interventions aimed at improving the nursing work environment: a systematic review. Implement Sci. 2010;5:34.20423492
17 Aiken LH, Clarke SP, Sloane DM, . Nurses’ reports on hospital care in five countries. Health Aff (Millwood). 2001;20(3):43–53.
18 Aiken LH, Clarke SP, Sloane DM, . Hospital nurse staffing and patient mortality, nurse burnout, and job dissatisfaction. JAMA. 2002;288(16):1987–93.12387650
19 Institute of Medicine (US) Committee on the Work Environment for Nurses and Patient Safety, Page A, eds. Keeping Patients Safe: Transforming the Work Environment of Nurses. Washington, D.C.: National Academies Press; 2004.
20 Rodriguez-Garcia MC, Marquez-Hernandez VV, Belmonte-Garcia T, . Original Research: How Magnet Hospital Status Affects Nurses, Patients, and Organizations: A Systematic Review. Am J Nurs. 2020;120(7):28–38.
21 Brooks Carthon JM, Hatfield L, Brom H, . System-Level Improvements in Work Environments Lead to Lower Nurse Burnout and Higher Patient Satisfaction. Journal of Nursing Care Quality. 2021;36(1).
22 US Department of Veterans Affairs. Veterans Health Administration (Homepage). Vol. 2025; 2025.
23 Dolansky MA, Moore SM. Quality and Safety Education for Nurses (QSEN): The Key is Systems Thinking. Online J Issues Nurs. 2013;18(3):1.
24 McGowan J, Sampson M, Salzwedel DM, . PRESS Peer Review of Electronic Search Strategies: 2015 Guideline Statement. J Clin Epidemiol. 2016;75:40–6.27005575
25 National Institutes of Health. Study Quality Assessment Tools. 2013.
26 Critical Appraisal Skills Programme CASP Qualitative Studies Checklist.
27 Sorra J GL, Streagle S, . AHRQ Hospital Survey on Patient Safety Culture: User’s Guide. AHRQ Publication No. 18-0036-EF (Replaces 04-0041, 15(16)-0049-EF). Rockville, MD: Agency for Healthcare Research and Quality. 2018.
28 Lake ET. Development of the practice environment scale of the Nursing Work Index. Res Nurs Health. 2002;25(3):176–88.12015780
29 Borenstein M. Introduction to meta-analysis Chichester, U.K.: John Wiley & Sons; 2009.
30 Peterson RA, Brown SP. On the use of beta coefficients in meta-analysis. J Appl Psychol. 2005;90(1):175–81.15641898
31 Rover C, Knapp G, Friede T. Hartung-Knapp-Sidik-Jonkman approach and its modification for random-effects meta-analysis with few studies. BMC Med Res Methodol. 2015;15:99.26573817
32 Hartung J, Knapp G. On tests of the overall treatment effect in meta-analysis with normally distributed responses. Stat Med. 2001;20(12):1771–82.11406840
33 Viechtbauer W. Conducting Meta-Analyses in R with the metafor Package. Journal of Statistical Software. 2010;36(3):1 – 48.
34 Ames H, Glenton C, Lewin S. Purposive sampling in a qualitative evidence synthesis: a worked example from a synthesis on parental perceptions of vaccination communication. BMC Med Res Methodol. 2019;19(1):26.30704402
35 Ames HM, Glenton C, Lewin S. Parents’ and informal caregivers’ views and experiences of communication about routine childhood vaccination: a synthesis of qualitative evidence. Cochrane Database Syst Rev. 2017;2(2):CD011787.28169420
36 Guyatt GH, Oxman AD, Vist GE, . GRADE: an emerging consensus on rating quality of evidence and strength of recommendations. Bmj. 2008;336(7650):924–6.18436948
37 Lewin S, Booth A, Glenton C, . Applying GRADE-CERQual to qualitative evidence synthesis findings: introduction to the series. Implement Sci. 2018;13(Suppl 1):2.29384079
38 Aiken LH, Sermeus W, McKee M, . Physician and nurse well-being, patient safety and recommendations for interventions: cross-sectional survey in hospitals in six European countries. BMJ open. 2024;14(2):e079931.
39 Bruyneel A, Bouckaert N, Pirson M, . Unfinished nursing care in intensive care units and the mediating role of the association between nurse working environment, and quality of care and nurses’ wellbeing. Intensive & critical care nursing. 2024;81(bg4, 9211274):103596.38043435
40 Campbell AR, Kennerly S, Swanson M, . Manager’s influence on the registered nurse and nursing assistant relational quality and patient safety culture. Journal of nursing management. 2021;29(8):2423–2432.34272913
41 Cho H, Steege LM, Arsenault Knudsen EN. Psychological safety, communication openness, nurse job outcomes, and patient safety in hospital nurses. Research in nursing & health. 2023;46(4):445–453.37370217
42 Fitzpatrick C, Buckingham T, Merrell J, . Engaging nurses in research and quality improvement is associated with higher job satisfaction and lower rates of unscheduled time off work: A pilot study. International journal of STD & AIDS. 2020;31(7):702–704.32448075
43 Forbes Iii TH. Understanding the peer, manager, and system influence on patient safety: A unique view of the Hospital Survey on Patient Safety Culture. Nursing Management. 2020;51(12):36–42.
44 Gurkova E, Kalankova D, Kurucova R, . Assessment of patient safety climate by nurses in Slovak Public and private hospitals. Journal of nursing management. 2020;28(7):1644–1652.32757476
45 Higashibata T, Hamano J, Nagaoka H, . Work environmental factors associated with compassion satisfaction and end-of-life care quality among nurses in general wards, palliative care units, and home care settings: A cross-sectional survey. International journal of nursing studies. 2023;143(gs8, 0400675):104521.37201336
46 Jedrzejczyk M, Guzak B, Czapla M, . Rationing of nursing care in Internal Medicine Departments-a cross-sectional study. BMC nursing. 2023;22(1):455.38044434
47 Kim S, Lynn MR, Baernholdt M, . How Does Workplace Violence–Reporting Culture Affect Workplace Violence, Nurse Burnout, and Patient Safety? Journal of Nursing Care Quality. 2023;38(1):11–18.36409656
48 Kim SY, Ko Y. Influence of the Team Effectiveness of Nursing Units on Nursing Care Left Undone and Nurse-Reported Quality of Care. Healthcare (Basel, Switzerland). 2023;11(10).
49 Kurucová R, Kalánková D, Žuffov A, . Hospital patient safety culture in selected Slovak hospitals: a cross-sectional study. Kontakt. 2022;24(4):273–278.
50 Lee SE, Dahinten VS. The Enabling, Enacting, and Elaborating Factors of Safety Culture Associated With Patient Safety: A Multilevel Analysis. Journal of nursing scholarship : an official publication of Sigma Theta Tau International Honor Society of Nursing. 2020;52(5):544–552.32573867
51 Lee SE, Dahinten VS. Using Dominance Analysis to Identify the Most Important Dimensions of Safety Culture for Predicting Patient Safety. International journal of environmental research and public health. 2021;18(15).
52 Malinowska-Lipien I, Micek A, Gabrys T, . Impact of the Work Environment on Patients’ Safety as Perceived by Nurses in Poland-A Cross-Sectional Study. International journal of environmental research and public health. 2021;18(22).
53 Montgomery AP, Patrician PA, Azuero A. Nurse Burnout Syndrome and Work Environment Impact Patient Safety Grade. Journal of nursing care quality. 2022;37(1):87–93.34149033
54 Muir KJ, Sloane DM, Aiken LH, . The association of the emergency department work environment on patient care and nurse job outcomes. Journal of the American College of Emergency Physicians open. 2023;4(5):e13040.37781503
55 Ozer O, Santas F. Effects of electronic medical records on patient safety culture: The perspective of nurses. Journal of evaluation in clinical practice. 2020;26(1):72–78.31190405
56 Pogue CA, Li P, Swiger P, . Associations among the nursing work environment, nurse-reported workplace bullying, and patient outcomes. Nursing forum. 2022;57(6):1059–1068.35908259
57 Seo JK, Lee SE. Improving Patient Safety and Care Quality Through a “Speaking-Up” Climate: The Mediating Role of Situation Monitoring. Risk management and healthcare policy. 2024;17(101566264):2035–2043.39220176
58 Shafran Tikva S, Gabay G, Shkoler O, . Association of quality of nursing care with violence load, burnout, and listening climate. Israel journal of health policy research. 2024;13(1):22.38659017
59 Smith S, Lapkin S, Sim J, . Nursing care left undone, practice environment and perceived quality of care in small rural hospitals. Journal of nursing management. 2020;28(8):2166–2173.32034965
60 Thomas-Hawkins C, Flynn L, Dillon J. Registered Nurse Staffing, Workload, and Nursing Care Left Undone, and Their Relationships to Patient Safety in Hemodialysis Units. Nephrology nursing journal : journal of the American Nephrology Nurses’ Association. 2020;47(2):133–142.32343087
61 Vincelette C, D’Aragon F, Stevens L-M, . The characteristics and factors associated with omitted nursing care in the intensive care unit: A cross-sectional study. Intensive & critical care nursing. 2023;75(bg4, 9211274):103343.36371393
62 Zaheer S, Ginsburg L, Wong HJ, . Acute care nurses’ perceptions of leadership, teamwork, turnover intention and patient safety - a mixed methods study. BMC nursing. 2021;20(1):134.34330272
63 Fekonja Z, Kmetec S, Fekonja U, . Emergency triage nurses’ perceptions of caring behaviors and the safety of the patient during triage encounters: a grounded theory study. BMC Nursing. 2024;23(1):1–11.38163872
64 Granel-Gimenez N, Palmieri PA, Watson-Badia CE, . Patient Safety Culture in European Hospitals: A Comparative Mixed Methods Study. International journal of environmental research and public health. 2022;19(2).
65 Hannawa AF, Wu AW, Kolyada A, . The aspects of healthcare quality that are important to health professionals and patients: A qualitative study. Patient Education & Counseling. 2022;105(6):1561–1570.34711447
66 Jones A, Johnstone M-J. Managing gaps in the continuity of nursing care to enhance patient safety. Collegian. 2019;26(1):151–157.
67 Kaldal MH, Feo R, Conroy T, . New graduate nurses’ delivery of patient care: A focused ethnography. Journal of Clinical Nursing (John Wiley & Sons, Inc.). 2023;32(19/20):7454–7466.
68 Nyberg A, Olofsson B, Fagerdahl A, . Longer work experience and age associated with safety attitudes in operating room nurses: an online cross-sectional study. BMJ open quality. 2024;13(1).
69 Peart T, Kerr D, Searby A. Novice nurses’ experiences in provision of mental ill health care within a regional emergency department: A descriptive qualitative study. International Journal of Mental Health Nursing. 2023;32(2):458–468.36562518
70 Peet J, Goodwin M, Nelson S, . Patient safety — Are we speaking the same language? Collegian. 2024;31(5):284–291.
71 Roche SD, Reichheld AM, Demosthenes N, . Measuring the quality of inpatient specialist consultation in the intensive care unit: Nursing and family experiences of communication. PloS one. 2019;14(4):e0214918.30973891
72 Ryan C, Powlesland J, Phillips C, . Nurses’ Perceptions of Quality Care. Journal of nursing care quality. 2017;32(2):180–185.27482871
73 Stavropoulou A, Rovithis M, Kelesi M, . What Quality of Care Means? Exploring Clinical Nurses’ Perceptions on the Concept of Quality Care: A Qualitative Study. Clin. Pract. 2022;12(4):468–481.35892437
74 Vinckx M-A, Bossuyt I, Dierckx de Casterlé B. Understanding the complexity of working under time pressure in oncology nursing: A grounded theory study. International Journal of Nursing Studies. 2018;87:60–68.30055374
75 Aiken LH, Sloane D, Griffiths P, . Nursing skill mix in European hospitals: cross-sectional study of the association with mortality, patient ratings, and quality of care. BMJ quality & safety. 2017;26(7):559–568.
76 Aiken LH, Sloane DM, Barnes H, . Nurses’ And Patients’ Appraisals Show Patient Safety In Hospitals Remains A Concern. Health affairs (Project Hope). 2018;37(11):1744–1751.30395515
77 Anzai E, Douglas C, Bonner A. Nursing practice environment, quality of care, and morale of hospital nurses in Japan. Nursing & Health Sciences. 2014;16(2):171–178.23855754
78 Auer C, Schwendimann R, Koch R, . How hospital leaders contribute to patient safety through the development of trust. The Journal of nursing administration. 2014;44(10 Suppl):S38–44.25279511
79 Ball J, Day T, Murrells T, . Cross-sectional examination of the association between shift length and hospital nurses job satisfaction and nurse reported quality measures. BMC nursing. 2017;16(101088683):26.28559745
80 Bartoníčková D, Kalánková D, Mikšová Z, . Patient safety culture from a nursing point of view in a broader context. Kontakt. 2019;21(2):121–127.
81 Cetin-Sahin D, McCusker J, Ciampi A, . Front-line emergency department nurses’ and physicians’ assessments of processes of elder-friendly care for quality improvement. International emergency nursing. 2021;58(101472191):101049.34509169
82 Cho E, Lee N-J, Kim E-Y, . Nurse staffing level and overtime associated with patient safety, quality of care, and care left undone in hospitals: A cross-sectional study. International journal of nursing studies. 2016;60(gs8, 0400675):263–71.27297386
83 Cho H, Pavek K, Steege L. Workplace verbal abuse, nurse-reported quality of care and patient safety outcomes among early-career hospital nurses. Journal of nursing management. 2020;28(6):1250–1258.32564407
84 Choi J, Miller P. Registered Nurse Perception of Patient Assignment Linking to Working Conditions and Outcomes. Journal of nursing scholarship : an official publication of Sigma Theta Tau International Honor Society of Nursing. 2018;50(5):530–539.30043443
85 Cline DD, Dickson VV, Kovner C, . Factors Influencing RNs’ Perceptions of Quality Geriatric Care in Rural Hospitals. Western journal of nursing research. 2014;36(6):748–68.24319004
86 Collier SL, Fitzpatrick JJ, Siedlecki SL, . Employee Engagement and a Culture of Safety in the Intensive Care Unit. JONA: The Journal of Nursing Administration. 2016;46(1):49–54.
87 Flynn L. Extending work environment research into home health settings. Taylor and Francis; 2016:55–61.
88 Goebel JR, Guo W, Wood KA. Teamwork and Perceptions of Palliative Care Quality. Journal of Hospice & Palliative Nursing. 2016;18(3):242–248.
89 Granel N, Manresa-Dominguez JM, Watson CE, . Nurses’ perceptions of patient safety culture: a mixed-methods study. BMC health services research. 2020;20(1):584.32590990
90 Griffiths P, Dall’Ora C, Simon M, . Nurses’ shift length and overtime working in 12 European countries: the association with perceived quality of care and patient safety. Medical care. 2014;52(11):975–81.25226543
91 Güneş ÜY, Gürlek Ö, Sönmez M. A survey of the patient safety culture of hospital nurses in Turkey. Collegian. 2016;23(2):225–232.
92 Havaei FM, Ji XRM, Boamah SA. Workplace Predictors of Quality and Safe Patient Care Delivery Among Nurses Using Machine Learning Techniques. Journal of Nursing Care Quality. 2022;37(2):103–109.34593739
93 Kim S, Mayer C, Jones CB. Relationships between nurses’ experiences of workplace violence, emotional exhaustion and patient safety. Journal of research in nursing : JRN. 2021;26(1–2):35–46.35251222
94 Ko Y, Yu S. The Relationships Among Perceived Patients’ Safety Culture, Intention to Report Errors, and Leader Coaching Behavior of Nurses in Korea: A Pilot Study. Journal of patient safety. 2017;13(3):175–183.26101999
95 Kristensen S, Hammer A, Bartels P, . Quality management and perceptions of teamwork and safety climate in European hospitals. Int. J. Qual. Health Care. 2015;27(6):499–506.26443813
96 Kutney-Lee A, Sloane DM, Bowles KH, . Electronic Health Record Adoption and Nurse Reports of Usability and Quality of Care: The Role of Work Environment. Applied clinical informatics. 2019;10(1):129–139.30786302
97 Kwan MR, Seo HJ, Lee SJ. The association between experience of hospital accreditation and nurses’ perception of patient safety culture in South Korean general hospitals: a cross-sectional study. BMC nursing. 2021;20(1):195.34641880
98 Laschinger HKS. Impact of workplace mistreatment on patient safety risk and nurse-assessed patient outcomes. The Journal of nursing administration. 2014;44(5):284–90.24759201
99 Lee SE, Vincent C, Dahinten VS, . Effects of Individual Nurse and Hospital Characteristics on Patient Adverse Events and Quality of Care: A Multilevel Analysis. Journal of Nursing Scholarship. 2018;50(4):432–440.29902354
100 Louch G, O’Hara J, Gardner P, . The daily relationships between staffing, safety perceptions and personality in hospital nursing: A longitudinal on-line diary study. International journal of nursing studies. 2016;59(gs8, 0400675):27–37.27222447
101 Lucas P, Jesus E, Almeida S, . Relationship of the nursing practice environment with the quality of care and patients’ safety in primary health care. BMC nursing. 2023;22(1):413.37915013
102 Ma C, Olds DM, Dunton NE. Nurse work environment and quality of care by unit types: A cross-sectional study. International journal of nursing studies. 2015;52(10):1565–72.26166148
103 Ma C, Shang J, Bott MJ. Linking Unit Collaboration and Nursing Leadership to Nurse Outcomes and Quality of Care. The Journal of nursing administration. 2015;45(9):435–42.26301550
104 Oh H, Uhm D-C, Yoon YJ. Workplace Bullying, Job Stress, Intent to Leave, and Nurses’ Perceptions of Patient Safety in South Korean Hospitals. Nursing research. 2016;65(5):380–8.27579505
105 Purpora C, Blegen MA, Stotts NA. Hospital staff registered nurses’ perception of horizontal violence, peer relationships, and the quality and safety of patient care. Work (Reading, Mass.). 2015;51(1):29–37.24939123
106 Ruppel H, Dougherty M, Bonafide CP, . Alarm burden and the nursing care environment: a 213-hospital cross-sectional study. BMJ open quality. 2023;12(4).
107 Sharp L, Rannus K, Olofsson A, . Patient safety culture among European cancer nurses-An exploratory, cross-sectional survey comparing data from Estonia, Germany, Netherlands, and United Kingdom. Journal of advanced nursing. 2019;75(12):3535–3543.31441110
108 Shin JI, Lee E. The effect of social capital on job satisfaction and quality of care among hospital nurses in South Korea. Journal of nursing management. 2016;24(7):934–942.27197700
109 Sloane DM, Smith HL, McHugh MD, . Effect of Changes in Hospital Nursing Resources on Improvements in Patient Safety and Quality of Care. Med. Care. 2018;56(12):1001–1008.30363019
110 Sonğur C, Özer Ö, Gün Ç, . Patient Safety Culture, Evidence-Based Practice and Performance in Nursing. Syst. Pract. Action Res. 2018;31(4):359–374.
111 Sováriová Soósová M. Association Between Nurses’ Burnout, Hospital Patient Safety Climate and Quality of Nursing Care. Central European Journal of Nursing & Midwifery. 2021;12(1):245–256.
112 Spence Laschinger HK, Fida R. Linking Nurses’ Perceptions of Patient Care Quality to Job Satisfaction. JONA: The Journal of Nursing Administration. 2015;45(5):276–283.
113 Spence Laschinger HK, Read E, Wilk P, . The influence of nursing unit empowerment and social capital on unit effectiveness and nurse perceptions of patient care quality. The Journal of nursing administration. 2014;44(6):347–52.24853796
114 Spence Laschinger HK, Zhu J, Read E. New nurses’ perceptions of professional practice behaviours, quality of care, job satisfaction and career retention. Journal of nursing management. 2016;24(5):656–65.26932145
115 Stalpers D, Van Der Linden D, Kaljouw MJ, . Nurse-perceived quality of care in intensive care units and associations with work environment characteristics: a multicentre survey study. Journal of advanced nursing. 2017;73(6):1482–1490.28000300
116 Stimpfel AW, Djukic M, Brewer CS, . Common predictors of nurse-reported quality of care and patient safety. Health care management review. 2019;44(1):57–66.28263207
117 Stimpfel AW, Rosen JE, McHugh MD. Understanding the role of the professional practice environment on quality of care in Magnet R and non-Magnet hospitals. The Journal of nursing administration. 2014;44(1):10–6.24316613
118 Top M, Tekingündüz S. Patient Safety Culture in a Turkish Public Hospital: A Study of Nurses’ Perceptions About Patient Safety. Syst. Pract. Action Res. 2015;28(2):87–110.
119 Van Bogaert P, Van heusden D, Somers A, . The Productive Ward program TM: a longitudinal multilevel study of nurse perceived practice environment, burnout, and nurse-reported quality of care and job outcomes. The Journal of nursing administration. 2014;44(9):452–61.25148399
120 Vifladt A, Simonsen BO, Lydersen S, . Changes in patient safety culture after restructuring of intensive care units: Two cross-sectional studies. Intensive & critical care nursing. 2016;32(bg4, 9211274):58–65.26604040
121 Viscardi MK, French R, Brom H, . Care Quality, Patient Safety, and Nurse Outcomes at Hospitals Serving Economically Disadvantaged Patients: A Case for Investment in Nursing. Policy, politics & nursing practice. 2022;23(1):5–14.
122 Weigl M, Schneider A. Associations of work characteristics, employee strain and self-perceived quality of care in Emergency Departments: A cross-sectional study. International emergency nursing. 2017;30(101472191):20–24.27524107
123 Yilmaz A, Duygulu S. The Relationship Between Charge Nurses and Clinical Nurses’ Perceptions of Patient Safety Culture and Leadership Practices. EJ. Dokuz. Eylul. Univ. Nurs. Fac. 2021;14(1):29–37.
124 Berntsson K, Eliasson M, Beckman L. Patient safety when receiving telephone advice in primary care - a Swedish qualitative interview study. BMC nursing. 2022;21(1):24.35042483
125 Bishop AC, Macdonald M. Patient Involvement in Patient Safety: A Qualitative Study of Nursing Staff and Patient Perceptions. Journal of patient safety. 2017;13(2):82–87.25010194
126 Ganz FD, Sapir B. Nurses’ perceptions of intensive care unit palliative care at end of life. Nursing in critical care. 2019;24(3):141–148.30426607
127 Giltenane M, Sheridan A, Kroll T, . Work environment challenging Irish public health nurses’ care quality: First postnatal visit. Public health nursing (Boston, Mass.). 2022;39(1):202–213.34672017
128 Kaczorowski KM, Drayton NA, Grimston MR. Gaining perspective into the term ‘safety culture’; how emergency nurses view its meaning in their everyday practice: a focus group study in an Australian setting. Australasian emergency care. 2020;23(1):1–5.32113919
129 Kanerva A, Kivinen T, Lammintakanen J. Communication elements supporting patient safety in psychiatric inpatient care. Journal of Psychiatric & Mental Health Nursing (John Wiley & Sons, Inc.). 2015;22(5):298–305.
130 Karlsson AC, Gunningberg L, Bäckström J, . Registered nurses’ perspectives of work satisfaction, patient safety and intention to stay – A double-edged sword. Journal of Nursing Management. 2019;27(7):1359–1365.31211908
131 Khalil H, Lee S. Medication safety challenges in primary care: Nurses’ perspective. Journal of Clinical Nursing (John Wiley & Sons, Inc.). 2018;27(9–10):2072–2082.
132 Kieft RA, de Brouwer BBJM, Francke AL, . How nurses and their work environment affect patient experiences of the quality of care: a qualitative study. BMC health services research. 2014;14(101088677):249.24923663
133 Tarling M, Jones A, Murrells T, . Comparing safety climate for nurses working in operating theatres, critical care and ward areas in the UK: A mixed methods study. BMJ Open. 2017;7(10).
134 Thompson E, Senek M, Ryan T. Analysis of a nursing survey: Reasons for compromised quality of care in inpatient mental health wards. International journal of mental health nursing. 2024;33(1):52–61.37654077
135 Van Bogaert P, Peremans L, Van Heusden D, . Predictors of burnout, work engagement and nurse reported job outcomes and quality of care: A mixed method study. BMC Nurs. 2017;16(1).
136 Wilson N, Jehn M, Kisana H, . Nurses’ Perceptions of Implant Barcode Scanning in Surgical Services. Computers, informatics, nursing : CIN. 2020;38(3):131–138.31688090
137 Zadvinskis IM, Chipps E, Yen P-Y. Exploring nurses’ confirmed expectations regarding health IT: a phenomenological study. International journal of medical informatics. 2014;83(2):89–98.24321515
138 Brann MJ. Improving unit performance with a staff-driven peer review process. Nursing forum. 2015;50(2):63–8.24404984
139 Despotou G, Her J, Arvanitis TN. Nurses’ Perceptions of Joint Commission International Accreditation on Patient Safety in Tertiary Care in South Korea: A Pilot Study. Journal of Nursing Regulation. 2020;10(4):30–36.
140 Dunn AS, Reyna M, Radbill B, . The Impact of Bedside Interdisciplinary Rounds on Length of Stay and Complications. Journal of hospital medicine. 2017;12(3):137–142.28272588
141 Kagan I, Fish M, Farkash-Fink N, . Computerization and its contribution to care quality improvement: The nurses’ perspective. International Journal of Medical Informatics. 2014;83(12):881–888.25176353
142 Magill ST, Wang DD, Rutledge WC, . Changing Operating Room Culture: Implementation of a Postoperative Debrief and Improved Safety Culture. World neurosurgery. 2017;107(101528275):597–603.28843757
143 Stallings-Welden LM, Shirey MR. Predictability of a Professional Practice Model to Affect Nurse and Patient Outcomes. Nursing administration quarterly. 2015;39(3):199–210.26049597
144 Vleminckx S, Van Bogaert P, Daneels K, . Strategies and Interventions to Support Quality Outcomes in the Home Care Setting: A Longitudinal Multilevel Study. The Journal of nursing administration. 2024;54(5):278–285.38648361
145 Wagner JIJ, MacPhee M, Udod S, . Surveys conducted pre- and post-implementation of a synergy tool: Giving voice to emergency teams. Journal of nursing management. 2021;29(6):1771–1777.33772912
146 Wei H, Sewell KA, Woody G, . The state of the science of nurse work environments in the United States: A systematic review. Int J Nurs Sci. 2018;5(3):287–300.31406839
147 Williams KM, Campbell CM, House S, . Healthy work environment: A systematic review informing a nursing professional practice model in the US Military Health System. J Adv Nurs. 2024;80(9):3565–3576.38469941
148 Dierkes A, Do D, Morin H, . The impact of California’s staffing mandate and the economic recession on registered nurse staffing levels: A longitudinal analysis. Nurs Outlook. 2022;70(2):219–227.34920888
149 Association TAN. American Nurses Association Supports the Nurse Staffing Standards for Hospital Patient Safety and Quality Care Act. 2023.
150 Brown LM, Lensing SY, Sullivan SC, . Evaluating the staffing methodology model in the veterans health administration’s community living centers. Geriatr Nurs. 2022;45:188–192.35512508
151 Min A, Scott LD. Evaluating nursing hours per patient day as a nurse staffing measure. J Nurs Manag. 2016;24(4):439–48.26576931
152 Rafi’i MR, Hanif SAM, Bin Daud F. Exploring the link between healthcare organizational culture and provider work satisfaction: a systematic review. BMC Health Serv Res. 2025;25(1):904.40611118