# ACKNOWLEDGMENTS

The authors are grateful to Becky Baltich Nelson for literature searching, Dr. Stacy Lavin for editorial support, Dr. Dazhe Chen, Dr. Rachel Pace, and Yung-Fang Deng for citation screening efforts, and the external peer reviewers. This work was partially supported by the Durham Center of Innovation to Accelerate Discovery and Practice Transformation (ADAPT) (CIN 13-410) at the Durham VA Health Care System, VA Office of Academic Affiliation Postdoctoral Fellowship in Health Systems Research (TPH 21-000), and VA Office of Academic Affiliation Quality Scholars Program (OAA Program AF-3Q-05-2019-C). The authors are also grateful to the following individuals for their contributions to this project.

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Sheila Cox Sullivan, PhD, RN, EBP-C, FAAN
  Director
  Research EBP & Analytics, Office of Nursing Services

## Technical Expert Panel

To ensure robust, scientifically relevant work, the technical expert panel (TEP) guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members included:

- Ann Kutney-Lee, PhD, RN, FAAN
  Research Scientist
  VA Center for Health Equity Research and Promotion (CHERP)

- Sarah Krein, PhD, RN
  Research Scientist
  VA Ann Arbor Center for Clinical Management Research

- Patricia A. Patrician, PhD, RN, FAAN
  Professor of Nursing, Nursing Family, Community & Health Systems (Chair)
  University of Alabama at Birmingham

- Amelia Schlak, PhD, RN
  Scientific Program Manager
  Health Services Research Portfolio, Office of Research and Development Veterans Health Administration, Department of Veteran Affairs