# Executive Summary

KEY FINDINGS

We identified 110 eligible studies that explored the relationship between the nurse work environment and nurses’ evaluations of health care quality or patient safety. For this review, we operationalized the concept of nurse work environment through an established taxonomy of 14 factors: teamwork, leadership, nurse autonomy, staffing adequacy, clarity of roles and goals, recognition, physical comfort, flexible scheduling, organizational stability or culture, professional development opportunities, salary, participation in decision-making, innovation, and workplace safety and violence. We used 3 evidence synthesis methods encompassing the following key questions (KQ):

► KQ1a: quantitative systematic review synthesizing the associations between nurse work environment on nurse-rated quality and safety (k = 76);
► KQ1b: qualitative evidence synthesis that synthesized how nurses perceived their work environment impacted quality and safety (k = 25); and
► KQ2: adapted evidence map of nurse work environment interventions (k = 9).
► Most of the quantitative studies for KQ1 were rated as having significant risk of bias concerns.
► We sampled qualitative studies for KQ1b based on the conceptual richness of findings; there were limited studies of sufficient richness identified.
► Across all KQs, no studies were conducted within the VA health care system.
► We identified a lack of nurse work environment interventions to improve nurse-rated health care quality and safety. Of those found, all focused on multiple work environment factors.

For both health care quality and patient safety outcomes for KQ1a, meta-analysis demonstrated a significant and positive association with multidimensional global measures of nurse work environment; these summary associations were of medium magnitude. Results for individual work environment factors were mixed.

► Health care quality: Only 4 work environment factors (ie, staffing adequacy, professional development, participation in decision-making, workplace safety and violence) evidenced significant association with nurse-rated health care quality; the magnitude of the associations were generally small.
► Patient safety: Of the 12 individual workplace factors with patient safety outcomes, 10 demonstrated significant associations with nurse-rated patient safety; only salary and participation in decision-making did not support significant associations with safety.
► Findings should be interpreted with some caution; the certainty of evidence was downgraded to very low certainty for inconsistency and for risk of bias across studies.

Findings from the qualitative evidence synthesis (KQ1b) complement those of the quantitative systematic review (KQ1a) and explore possible mechanisms for how individual workplace factors may impact nurses’ perceptions of quality and patient safety.

► Key features of staffing adequacy that are important to nurses in delivering high-quality care and assuring patient safety include nurse experience, patient-to-nurse ratios, patient acuity, use of overtime, and staffing mix during shifts.
► Communication skills, shared team processes, and positive relationships and cohesion among team members were expressed to be important drivers of quality and safety.
► Nurses expressed that leadership played a pivotal role in their perceptions of quality and safety. Effective leaders facilitated quality and safety by securing needed resources and setting a tone that supports quality care and patient safety culture. Having a leader who trusts frontline nursing staff was an important ingredient in a supportive nurse work environment.

The nursing workforce is a key component of health care systems and is essential in assuring high-quality care and patient safety. Nurse-rated quality of care has been used as a research measure for decades and is recognized globally by nurse researchers as a valid and reliable measure. Multiple studies have reported significant association between objective measures of health care quality and nurse-rated quality of care. While there are many factors that contribute to health care quality and patient safety, the environment in which nurses perform their work plays a pivotal role. The nursing work environment is comprised of multiple characteristics, including physical features, organizational structures and policies, interpersonal factors, and organizational culture. The nurse work environment is distinct from work environment indicators (ie, signs of workforce health), such as job satisfaction, turnover, absenteeism, or burnout. Yet the work environment can influence these workforce indicators. Thus, attention to specific factors of the nursing work environment continues to be an important area of exploration to not only improve the quality of care experienced by patients but also buffer key nursing workforce indicators such as nurse burnout and job satisfaction.

## CURRENT REVIEW

The purpose of this review is to synthesize the literature exploring the relationship between nurse work environment factors and nurses’ quantitative and qualitative evaluations of health care quality patient safety. Findings will be used by the VA Office of Nursing Services to inform future data collection to monitor trends in VA nurse-rated quality of care, guide efforts to address nurse performance obstacles, and identify potential interventions to foster healthy nurse work environments to bolster the well-being of the VA nursing workforce and VA patients. Informed by an established taxonomy, we defined the nurse work environment to encompass 1 or more of 14 factors: teamwork, leadership, nurse autonomy, staffing adequacy, clarity of roles and goals, recognition, physical comfort, flexible scheduling, organizational stability or culture, professional development opportunities, salary, participation in decision-making, innovation, and workplace safety and violence. We addressed the following key questions in this review: (KQ1a) What is the impact of nurse work environment characteristics on nurse-rated health care quality and safety? (KQ1b) How do nurses perceive that their work environment impacts health care quality and safety? (KQ2) What nurse work environment interventions or strategies are available to improve nurse-rated health care quality and safety? We conducted COE ratings for the outcomes of quality and safety by work environment factors identified by key VA stakeholders and the TEP as critical to decision-making (ie, leadership, staffing adequacy, teamwork, nurse autonomy).

Of the 3,682 unique records evaluated for inclusion, 110 meet eligibility criteria. Of these, 76 evaluated how workplace factors affected nurse-rated quality of care and safety using a quantitative methodology (KQ1a); 25 studies evaluated nurses’ perceptions of quality of care and safety using a qualitative methodology (KQ1b); and 9 studies evaluated the effectiveness of interventions designed to improve working environments to impact nurse-rated quality of care and patient safety (KQ2). Nearly all the studies for KQ1a were cross-sectional designs, with the most common health care setting being the inpatient setting. For KQ1b, most studies were primarily qualitative designs, and the most common setting was the acute care inpatient setting. Across all KQs, we did not identify any studies that were conducted within the VA health care system. For the 110 eligible studies, we prioritized a subset of the included studies for synthesis of outcomes. Since our aim was to highlight the most relevant quantitative literature, we selected more recent studies for KQ1a resulting in an analytic dataset of 25 studies. For KQ1b, we sampled 12 of the 25 eligible studies based on the conceptual richness of study findings and to obtain representation across health care settings.

For our KQ1a, exploring the quantitative associations between nurse work environment factors and nurse-rated health care quality and patient safety, teamwork was the most frequently reported nurse work environment factor, with staffing adequacy and leadership the next most reported factors. We were able to synthesize findings for nurse-rated health care quality among 10 of the 14 workplace factors.

- While meta-analysis demonstrated a positive association of moderate magnitude between global measures of work environment and health care quality (standardized regression weight [SRW] = 0.39, 95% CI [0.09, 0.68]), only 4 of 10 factors evidenced significant association with nurse-rated health care quality (ie, staffing adequacy, professional development, participation in decision-making, and workplace safety and violence), with the magnitude of associations generally small.
- Meta-analysis of global measures of workplace factors also demonstrated a positive association with nurse-rated patient safety (SRW = 0.42, 95% CI [0.13, 0.71]) of moderate magnitude. We were able to synthesize patient safety outcomes data on 12 workplace factors; we did not have data for clarity of roles and goals or recognition workplace factors. Of these 12 individual workplace factors with patient safety outcomes, 10 demonstrated significant associations with nurse-rated patient safety (ie, teamwork, leadership, nurse autonomy, staffing adequacy, physical comfort, flexible scheduling, organizational culture, professional development opportunities, innovation, and workplace safety and violence). Across these associations, effect estimates were generally small.
- Findings should be interpreted with some caution. Of the prioritized work environment factors, the COE ratings for teamwork, leadership, and staffing adequacy for quality and patient safety outcomes were low due to inconsistency and ROB in reported studies. We had insufficient data to assess COE for the nursing autonomy work factor for both quality and safety.

For KQ1b, exploring qualitative findings of how nurses perceive that their work environment impacts health care quality and patient safety, we were able to synthesize themes for 11 of the 14 workplace factors. Some salient findings are summarized here.

- Teamwork themes demonstrated the importance of communication skills required to function as a team, the importance of team relationships, and team cohesion in buffering work stressors.
- For leadership, themes centered on the importance of leadership in securing supplies and human resources and how effective communication skills can set a tone that supports a culture of quality and patient safety. Additionally, having a leader who trusts nursing staff was perceived as an important ingredient in a workplace that was supportive of health care quality and patient safety.
- For issues of nurse autonomy and safety, themes focused on how nurses perceived patient safety as their personal responsibility and their willingness to assertively advocate for the needs of their patients. Nurses expressed that they were more assertive patient advocates if they had more years on the job.
- Qualitative findings explored staffing adequacy features that are important to nurses (ie, nurse experience, patient-to-nurse ratios, patient acuity, use of overtime, and staffing mix during shift) and how staffing impacts quality and safety via task overload caused by staffing shortages.
- For organizational culture, themes focused on how culture of the unit shapes nurse attitudes, behaviors, practice patterns, and subsequent interactions with staff and patients. For patient safety, 2 themes underscore negative cultural factors: 1) how an organization’s response to an error impacts the culture of safety at a workplace; and 2) the transfer of patient safety accountability from the organization to frontline nursing staff. Two positive cultural themes were also derived from the data: 1) how experiencing trust and support, demonstrated through being listened to when expressing patient needs, fostered a safety culture; and 2) how a common communication system between staff and the organization signaled an organizational mission focused on patient safety.
- Across prioritized themes for leadership, teamwork, and staffing adequacy workplace factors, the COE for quality and safety outcomes was rated as high or moderate, suggesting stability in these findings. Both themes prioritized for COE for nurse autonomy (ie, independent practice expectations and age and experience) were rated as low confidence.

For KQ2 that summarized the characteristics nurse work environment interventions designed to improve on nurse-rated health care quality and safety, we found limited studies.

- Overall, we only identified 9 comparative studies. Most interventions focused on 3 or more workplace factors, with teamwork as the most common factor.
- While all interventions used unique packages of approaches tailored to the health care setting, all used some form of process improvement approaches that engaged the organizations’ leadership, and sought to enhance evaluation and feedback, training, and communication.

## CONCLUSIONS

Our findings support the importance of the nurse work environment on nurses’ quantitative ratings and qualitative perceptions of health care quality and patient safety. While there are limitations of this review, results suggest many promising approaches that health care administrators and nursing leadership may pursue to create supportive nursing work environments that foster quality care and patient safety. Yet, changing just 1 workplace factor is likely not sufficient to create robust impacts on quality and safety outcomes, as evidenced by our mixed findings and generally small associations across individual work environment factors. Our findings support that multidimensional measures of the nurse work environment are associated with significant and positive effects of moderate magnitude. Our qualitative findings support this assumption; there were several common qualitative themes across individual workplace factors that point to the importance of shared cultural beliefs, norms, and values. Also, the nascent intervention literature mapped in KQ2 suggests that tested interventions commonly intervened on 3 or more work environmental factors. Findings across our results suggest that nurse workplace factors are likely to be interconnected and influenced by the culture of the organization.