# DISCUSSION

There are many factors that contribute to the delivery of safe and high-quality care. One such well-studied factor contributing to health care quality and safety is the nursing work environment.^21,146,147^ In this report, we investigated the potential relationship between nurse work environment factors and nurse’s quantitative rating (KQ1a) and qualitative perceptions (KQ1b) of health care quality and patient safety through several evidence synthesis methods encompassing a quantitative systematic review, a qualitative evidence synthesis, and an adapted evidence map of nurse work environment interventions. We explore 3 distinct but complementary key questions: if nurse work environment factors impact nurse-rated health care quality and patient safety (KQ1a), how do nurses perceive the impact of these factors (KQ1b); and what intervention strategies have been implemented for improvements in the nurse work environment (KQ2). Informed by an established taxonomy,^16^ the nurse work environment included 14 individual factors: teamwork, leadership, nurse autonomy, staffing adequacy, clarity of roles and goals, recognition, physical comfort, flexible scheduling, organizational stability or culture, professional development opportunities, salary, participation in decision-making, innovation, and workplace safety and violence.

For our KQ1a exploring the quantitative associations between nurse work environment factors and nurse-rated health care quality and patient safety, teamwork was the most frequently reported nurse work environment factor, with staffing adequacy and leadership the next most reported factors. We were able to synthesize findings for nurse-rated health care quality among 10 of the 14 workplace factors. While meta-analysis demonstrated a positive association of moderate magnitude between global measures of work environment and health care quality (SRW = 0.39, 95% CI [0.09, 0.68]), only 4 of 10 factors evidenced significant association with nurse-rated health care quality (ie, staffing adequacy, professional development, participation in decision-making, workplace safety), with the magnitude of associations generally small. Like health care quality, meta-analysis of global measures of workplace factors also demonstrated a positive association with nurse-rated patient safety (SRW = 0.42 95% CI [0.13, 0.71]) of moderate magnitude. We were able to synthesize patient safety outcomes data on 12 workplace factors; we did not have data for clarity of roles and goals or recognition workplace factors. Of these 12 individual workplace factors with patient safety outcomes, only 2 did not demonstrate significant associations with nurse-rated patient safety (ie, salary, participation in decision-making). Across these associations, effect estimates were generally small. Yet findings should be interpreted with some caution. Of the work environment factors prioritized by our stakeholders, the COE ratings for teamwork, leadership, and staffing adequacy for quality and patient safety were low due to inconsistency and high ROB in reported studies; we had insufficient data to assess COE for the nursing autonomy work environment factor.

Findings from the qualitative evidence synthesis (KQ1b) complement our quantitative results as themes explore some possible mechanisms for how individual workplace factors may impact nurses’ perceptions of health care quality and patient safety. For example, the quantitative results suggest a small positive association of teamwork with both quality and safety but do not provide guidance for how to harness the power of teams. The qualitative findings for teamwork highlight the importance of skills required to function as a team (eg, communication skills, team processes) and the role of team cohesion in buffering work stressors. For leadership, themes for quality and safety centered on the role of leadership in securing resources (eg, sufficient staffing, physical supplies), and how effective communication skills create a culture that supports quality care and patient safety. Additionally, having leaders who trust frontline nursing staff was seen as an important ingredient in a supportive nurse workplace. While we identified limited quantitative studies focusing on nurse autonomy, qualitative findings underscore the tension nurses face between expectations of independent practice and seeking assistance in completing nursing tasks. For issues of safety, qualitative themes focused on how nurses perceived patient safety as their personal responsibility and their willingness to assertively advocate for the needs of their patients. Another theme expanded on nurse advocacy skills and underscored the importance of the nurse experience and use of assertive communication around patient safety at work.

Staffing adequacy was significantly associated with quality in safety in KQ1a; yet results provided little insight into how to optimize staffing. Qualitative themes elucidated staffing adequacy features that are important to nurses (ie, nurse experience, patient-to-nurse ratios, patient acuity, use of overtime, staffing mix during shift) and how staffing impacts outcomes via task overload caused by staffing shortages. For organizational culture, quantitative findings for health care quality found a small but not significant association, likely due to the multidimensional nature of workplace culture. Qualitative findings expanded these mixed quantitative results and explored how organizational culture of the unit shapes nurse attitudes, behaviors, practice patterns, and subsequent interactions with staff and patients. For patient safety, 2 themes underscore negative cultural factors: how an organization’s response to errors impacts the culture of safety at a workplace, and the transfer of patient safety accountability from the organization to frontline nursing staff. Yet there were also positive cultural themes that support patient safety. Nurses expressed that experiencing trust and support, demonstrated through being listened to when expressing patient needs, fostered a safety culture. A safety culture was also fostered by a common communication system between staff and the organization that signals the shared mission of a culture of patient safety.

We had limited to no findings for several workplace factors in KQ1a. However, qualitive findings from KQ1b provide some guidance on how these factors may be optimized to promote quality health care and a culture of patient safety across diverse health care settings. Qualitative themes for clarity of role and goals echoed other findings that focus on the personal responsibility that nurses perceived as part of their role in providing high quality and safe care to all patients. Themes related to recognition and quality include the provided evidence on the importance of positive feedback from patients and coworkers in increasing nurses’ job satisfaction. For physical comfort and health care quality, we found that nurses perceived high levels of environmental noises in the patient care setting as a barrier to completing nursing tasks and contributing to patient agitation. In comparison, themes related to physical comfort and patient safety were focused on the role of interruptions on providing safe care and the importance of having staff-specific physical spaces to take breaks from the demands of the job. While we found only limited quantitative studies exploring the importance of professional development opportunities, qualitative themes for both quality and safety demonstrated that nurses perceived such opportunities as essential in providing safe, high-quality health care. Like our quantitative findings, we identified limited qualitative studies exploring nurses’ perceptions of workplace safety and violence on health care quality and patient safety. These limited findings explored the role of nursing workplace safety as encompassing an environment that is free of bullying and violence for staff, patients, and family caregivers entering the health care setting. Across prioritized themes for leadership, teamwork, and staffing adequacy work factors, the COE for quality and safety outcomes was mostly rated as high or moderate, suggesting stability in these thematic findings. Only 1 quality theme for staffing adequacy (ie, nurse experience) and 1 patient safety theme for leadership (ie, leadership support) were rated as low or very low confidence, respectively, suggesting further studies may shift our confidence in the stability of these findings. Both themes prioritized for COE for nurse autonomy (ie, independent practice expectations, age and experience) were rated as low confidence, suggesting additional studies with more relevance may shift these findings.

We also had limited findings on nurse work environment interventions that sought to improve nurse-rated health care quality and patient safety (KQ2). Overall, we only identified 9 comparative studies. Most interventions focused on 3 or more workplace factors, with teamwork as the most common factor. These findings underscore the results of our quantitative systematic review (KQ 1a) which demonstrated most robust effect sizes for associations of multidimensional measures of work environment and quality and safety.

Our findings complement and extend findings of other systematic reviews on aligned topics. For example, 1 review summarized finding from qualitative and quantitative studies and simultaneously combined these evidence streams via a qualitative constant comparative method to develop 5 major themes on the impacts of healthy work environments on the following areas: 1) nurse outcomes (eg, emotional well-being, retention), 2) interpersonal relationships, 3) patient care quality, 4) hospital accidental safety, and 5) nurse leadership.^146^ This review was limited to studies conducted in the US published between 2005 and 2017. This review’s qualitative themes supported our quantitative findings on the importance of global multidimensional measures of work environment and their significant association with quality and patient safety. Similarly, our findings support the importance of leadership as a key work environment factor that supports quality and safety. Our findings extend their findings by quantifying the magnitude of these relationships and by qualitatively exploring importance of effective communication skills of leadership and how trust between leadership and nursing staff impacts the workplace culture. Another more recent review summarized the evidence on work environments to inform recommendations for creating healthy work environment for nurses in the US Military Health System.^147^ Authors’ results supported the key role of supportive leadership, professional development, participation in decision-making, and staffing adequacy, which we also found in our quantitative exploration of workplace factors. This review also identified teamwork as a key factor; our quantitative results demonstrated a small positive association, but summary estimates were not statistically significant for both the outcomes of nurse-rated quality and patient safety. Lastly, a systematic review published in 2010 synthesized the evidence on interventions aimed at improving nurse assessment of their work environment. This review also conducted a scoping review to develop a taxonomy of 14 workplace factors that informed the schema used in our report.^16^ Similar to our KQ2 findings, this review only identified 9 comparative studies. Similar to our results, this review found that teamwork was the most common workplace factor intervened upon, with a median of 4 workplace factors impacted (range = 1–7). Yet there are some key differences in our evidence mapping review and their systematic review. First, to be included in their review, a study had to have pre-post measures of nurse-rated work environment. We too needed pre-post assessment but centered on the outcomes of nurse-rated patient safety or health care quality, which may be more salient outcomes for health care policymakers. Next, their review provided information on which types of strategies impacted nurse workplace factors, while our review provided insights into specific organizational implementation strategies used to address the nurse work environment (eg, implementing tool for quality monitoring, audit, and feedback).

Taken together, our findings suggest several promising avenues that leadership and supervisors at various levels within health systems could explore to support a healthy nurse work environment, foster a culture of patient safety, and optimize the delivery of high-quality health care while buffering workplace stressors for nurses. When considering staffing, our review highlights the importance of holistic staffing adequacy over set ratios. Yet nurse-to-patient ratios may be impacted by legally required ratios.^148^ Although professional groups offer guidance and support,^149^ issues persist related to mandated staffing requirements that may not fully capture the key elements of staffing adequacy such as nursing staff experience, nurse skill, and shift length explored here. It is important to note that the VA does not have a relevant federal law mandating nurse-to-patient ratios in the hospital setting. Instead, the VHA uses a “staffing methodology” to determine appropriate levels of nursing staff in the hospital setting,^150^ a standardized method to determine nurse staffing needs based on the total nursing hours per patient day endorsed by the National Quality Forum.^151^ Next, it is important to acknowledge that nursing workplace factors are likely to be intertwined with, and influenced by, the culture of the organization. Our findings support this assumption; there were several common qualitative themes across individual workplace factors that point to the importance of shared cultural beliefs, norms, and values. Also, the global multidimensional work environment measures supported robust quantitative results for both health care quality and patient safety. Findings from our evidence map of nurse work environment interventions also suggest intervening on multiple workplace factors may be needed to foster meaningful impacts on patient safety and overall health care quality. Many studies have demonstrated the importance of health care organizational culture on important health system outcomes such as staff satisfaction.^152^ Several factors influence the culture of an organization, including leadership. Our review provides support for the critical role that leadership plays supporting nurses in delivering safe and quality care. Leaders have the means to set policy, offer professional development, and control staffing. Health care leaders can support leadership skills of those directly supervising frontline nurses and set the tone and vision of an organization, which influences cultural norms and subsequent behaviors within the organization. Lastly, it is worth noting that there were more statistically significant associations, with less statistical heterogeneity, between workplace factors and nurse-rated patient safety than there were between workplace factors and health care quality. This may suggest less variation in how nurses conceptualize patient safety across studies compared to how nurses conceptualize health care quality. Simply, patient safety may be a more stable nurse-rated metric than nurse-rated quality of care. Yet, patient safety is inherently a part of high-quality care. As such, health care leaders may want to identify tangible targets of health care quality analogous to concrete safety events to improve nurse evaluations of overall health care quality.

## LIMITATIONS

It is important to note limitations of both the identified literature and our approach to conducting this review. With respect to the identified literature, both the qualitative and quantitative studies identified here had multiple methodological limitations. Overall, there were few studies included for KQ1b with richness scores of 4 or greater, and nearly all studies for KQ1a were cross-sectional designs. Next, our search identified a paucity of research in the outpatient settings. In total, we identified only 6 potential studies with half of these studies conducted within an emergency department setting. Also, we identified only 1 study that described the impact of the electronic health record on nurse-rated quality and patient safety, suggesting more research is needed in this area. Next, we selected an a priori taxonomy of nurse work environment factors; such an approach may exclude other workplace factors not included in our 14-factor taxonomy. Also, while we used multiple approaches to enhance rigor and reproducibility of our findings (eg, use of multiple raters with consensus methods, audit trails), others may come to different conclusions about which measures are associated with a particular work environment exposure across individual studies. Also, we opted to only analyze a subset of eligible studies, which resulted in a small group of workplace factors that did not have findings despite having potentially eligible studies. As these decisions were made based on date limits for KQ1a and robustness of qualitative studies for KQ1b; these limitations were unknown until analyses were finalized. The outcomes included in this review were nurse self-reports of patient safety and health care quality, which have limitations. Yet there is growing evidence and support of person-reported outcomes in the health care setting and their correlation with other metrics of quality.^6^ It is important to note that studies identified from non-US health systems may not be representative of work environments found within the US, which is another limitation of our approach. Similarly, nurse work environments and scope of practice may vary by region within the US, and the identified literature may not be generalizable to every health system within the country.

## FUTURE RESEARCH

While nursing environments and nursing evaluations of care quality and patient safety have been studied, future research is needed to fully understand the relationship between these concepts (Table 30). Future interventional research in this area should focus on pragmatic approaches that leverage the assets of learning health systems to assess strategies to foster healthy work environment for nurses and combine multiple workplace factors that demonstrated significant or salient findings here. Although we disaggregated nurse work environment into 14 different factors, they are likely interconnected, influencing each other. Additional qualitative research is needed to understand nurses’ perspectives on their workplace and its relationship with quality and safety for which we found few studies. Of the studies we identified in this area, few directly intended to explore this relationship. The studies identified were also conducted in health care settings that may not be generalizable to VHA, given differences in nursing scopes of practice in studies conducted outside the VHA and the US.

Table 30 Recommendations for Future Research on Nursing Quality of Care

Domain | Study Design Targets for Future Research
Population | Nurses with different levels of job experience or professional training may perceive their work environments or care quality and patient safety differently.; Nurses providing care in different acuity settings may have unique perceptions of care, safety, and work environment.; Nurses who work within diverse settings within the VHA Health Care System.; As nursing scope of practice is recognized as having variability based on country of practice as well as regulatory bodies that drive differences in practice even between states in the US, need studies that explore how expanded scope of practice may impact nurse perceptions of autonomy and teamwork and thus impact generalizability to settings with more restrictive scopes of practice.
Intervention | Given the small association between individual workplace factors, need to assess intervention packages that intervene on multiple workplace factors that demonstrate the most robust associations on health care quality and patient safety.; Use of validated measures of work environment (eg, PES-NWI, HSOPSC).; Multi-component interventions that support and communicate an organizational culture of patient safety and quality health care.; Exploration of the impact of electronic health record documentation on nurse-rated quality and safety.; Pragmatic approaches that leverage the data infrastructure, learning communities, and continuous quality improvement cycles of learning health systems to measure outcomes in real time to advance the knowledge on promising interventions.
Comparator | Comparative designs with any comparator.; Muti-site interventions with at least 1 intervention and 1 control site and measurements taken before and after the workplace intervention.
Outcomes | Validated measures of perceptions of patient care (eg, HSPOPSC).; Additional aspects of the nurse experience such as those identified via qualitative nurse interviews.; Assessments of nurse-rated quality and patient safety in office-based outpatient setting.
Timing | Short and long-term outcomes relative to any interventions (eg, sustained workplace change).

## CONCLUSIONS

Our findings support the importance of the nurse workplace environment on nurses’ perceptions of health care quality and patient safety. While there are limitations of this review, results suggest many promising approaches that health care administrators and nursing leadership may pursue to create supportive nursing work environments that foster quality care and patient safety. Yet, changing just 1 element of the work environment is likely not sufficient to create robust impacts on quality and safety outcomes, as evidenced by our mixed findings and generally small associations across individual work environment factors. Our findings support that multidimensional measures of the nurse work environment are associated with significant and positive effects of moderate magnitude. Also, the nascent intervention literature mapped in KQ2 suggests that tested interventions commonly intervened on 3 or more environmental factors. Findings from our results suggest that nurse workplace factors are likely to be interconnected and influenced by the culture of the organization.