# RESULTS

## LITERATURE FLOW DIAGRAM

The literature flow diagram summarizes the results of the study selection process. A full list of excluded studies is provided in the Supplementary Materials.

Abbreviations. OECD=Organisation for Economic Cooperation Development countries.

Literature flow diagram summarizing results of study selection process.

## OVERVIEW OF INCLUDED STUDIES

Our search yielded 3,682 unique records, of which 110 met eligibility criteria. Among the eligible studies, 76 evaluated how workplace factors affected nurses’ perceptions of quality of care and safety using a quantitative methodology (KQ1a) (Table 4); 25 studies evaluated nurses’ perceptions of quality of care and safety using a qualitative methodology (KQ1b) (Table 5); and 9 studies evaluated the effectiveness of interventions designed to improve nursing working environments and, thus, nurse-rated quality of care and safety (KQ2). The 76 KQ1a studies consisted of 73 cross-sectional studies and 3 mixed-methods studies. The 25 KQ1b studies consisted of 17 qualitative studies, 9 mixed-methods studies, 1 cross-sectional study, and 1 ethnography. The 9 KQ2 studies consisted of 5 uncontrolled before-and-after studies, 1 controlled before-and-after study, 1 cross-sectional study, 1 prospective cohort study, and 1 interrupted time series. Since our aim was to highlight the most recent literature, 25 of the 76 KQ1a studies were prioritized for outcome data abstraction and synthesis because their study data had been collected since 2018 or published after 2017. Twelve of the 25 KQ1b studies were selected for outcome data abstraction and synthesis based on the richness of the qualitative data present in the study and the setting of the study. Across KQ1a, KQ1b, and KQ2, the most common country setting was the US, followed by Canada. We did not identify any studies that were conducted by VHA, nor any studies that described Veterans specifically.

Table 4 Evidence Profile for Key Question 1a

Study Characteristic | KQ1a (Total – Analytic and Non-Analytic) | KQ1a (Analytic Set Only)
Number of Studies | 76 | 25
Study Designs | Cross sectional (k = 73), mixed methods (k = 3) | Cross sectional (k = 24), mixed methods (k = 1)
Study Year Range | 2014–2024 | 2020–2024
Study Data Collection Year Range | 2009–2023 | 2018–2024
N | 593,440 | 77,735
Countries | Belgium (k = 5), England (k = 3), Finland (k = 2), Ireland (k = 3), Spain (k = 4), Switzerland (k = 3), Germany (k = 5), Sweden (k = 3), Norway (k = 3), Japan (k = 2), United Kingdom (k = 1), Czech Republic (k = 2), Austria (k = 1), Canada (k = 9), Korea (k = 7), Greece (k = 1), Netherlands (k = 3), Poland (k = 4), Turkey (k = 6), Portugal (k = 2), Israel (k = 1), Estonia (k = 1), Slovakia (k = 3), Australia (k = 1), United States (k = 26) | Belgium (k = 2), Korea (k = 2), Israel (k = 1), England (k = 1), Germany (k = 1), Ireland (k = 1), Sweden (k = 1), Norway (k = 1), Poland (k = 1), Canada (k = 2), Japan (k = 1), Austria (k = 1), Turkey (k = 1), United Kingdom (k = 1), Australia (k = 1), Slovakia (k = 2), United States (k = 9)
Settings | Procedural (inpatient) (k = 2), Mix (inpatient) (k = 35), Acute care (inpatient) (k = 13), Critical care [eg, ICU] (inpatient) (k = 6), Emergency room (outpatient) (k = 3), Home health and home visits (outpatient) (k = 1), Mixed (Inpatient and outpatient) (k = 9), Office primary care and specialty care (outpatient) (k = 2) | Critical care [eg, ICU] (inpatient) (k = 2), Emergency room (outpatient) (k = 1), Mix (inpatient) (k = 12), Mixed (Inpatient and outpatient) (k = 2), Acute care (inpatient) (k = 4), Procedural (inpatient) (k = 1)
Workplace Factors | Teamwork (k = 46), Leadership (k = 41), Staffing adequacy (k = 43), Participation in decision-making (k = 17), Organizational culture (k = 22), Nurse autonomy (k = 16), Global (k = 6), Recognition (k = 5), Clarity of roles and goals (k = 5), Salary (k = 1), Workplace safety (k = 10), Physical comfort (k = 10), Professional development opportunities (k = 13), Innovation (k = 8), Flexible scheduling (k = 5) | Teamwork (k = 10), Leadership (k = 10), Staffing adequacy (k = 11), Participation in decision-making (k = 3), Organizational culture (k = 9), Nurse autonomy (k = 2), Global (k = 6), Recognition (k = 2), Clarity of roles and goals (k = 0), Salary (k = 1), Workplace safety (k = 3), Physical comfort (k = 1), Professional development opportunities (k = 2), Innovation (k = 4), Flexible scheduling (k = 2)
Outcomes | Quality (k = 44); Safety (k = 53) | Quality (k = 12); Safety (k = 18)

Notes. Some studies were conducted in several countries, including non-OECD countries; thus, the total k across individual countries exceeds k of studies.

Abbreviations. OECD=Organisation for Economic Cooperation Development countries.

Table 5 Evidence Profile for Key Question 1b

Study Characteristic | KQ1b (Total – Analytic and Non-Analytic) | KQ1b Analytic Set Only
Number of Studies | 25 | 12
Study Designs | Qualitative (k = 17), Mixed methods (k = 6), Ethnography (k = 1), Cross sectional (k = 1) | Qualitative (k = 10), Mixed methods (k = 1), Ethnography (k = 1)
Study Year Range | 2014–2024 | 2017–2024
Study Data Collection Year Range | 2011–2022 | 2015–2022
N | 2,538 | 754
Countries | Canada (k = 2), Sweden (k = 4), Slovenia (k = 1), Israel (k = 1), Ireland (k = 1), Croatia*, Hungary (k = 1), Spain (k = 1), Switzerland (k = 1), Australia (k = 5), Denmark (k = 1), Finland (k = 1), Netherlands (k = 1), Greece (k = 1), United Kingdom (k = 1), Belgium (k = 2), United States (k = 3) | Denmark (k = 1), Belgium (k = 1), Sweden (k = 2), Australia (k = 3), Slovenia (k = 1), Greece (k = 1), Switzerland (k = 1), Croatia*, Hungary (k = 1), Spain (k = 1), United States (k = 2)
Settings | Home health and home visits (outpatient) (k = 1), Mix (inpatient) (k = 2), Emergency room (outpatient) (k = 3), Critical care [eg, ICU] (inpatient) (k = 1), Office primary care and specialty care (outpatient) (k = 1), Mixed (Inpatient and outpatient) (k = 4), Mix (outpatient) (k = 2), Acute care (inpatient) (k = 7), Procedural (inpatient) (k = 2), Long-term care [eg, hospice] (inpatient) (k = 1) | Acute care (inpatient) (k = 3), Procedural (inpatient) (k = 1), Emergency room (outpatient) (k = 2), Mixed (Inpatient and outpatient) (k = 4), Mix (outpatient) (k = 1), Critical care [eg, ICU] (inpatient) (k = 1)
Workplace Factors | Teamwork (k = 21), Leadership (k = 14), Staffing adequacy (k = 20), Participation in decision-making (k = 4), Organizational culture (k = 7), Nurse autonomy (k = 6), Global (k = 0), Recognition (k = 2), Clarity of roles and goals (k = 7), Salary (k = 1), Workplace safety (k = 4), Physical comfort (k = 10), Professional development opportunities (k = 8), Innovation (k = 1), Flexible scheduling (k = 1) | Teamwork (k = 11), Leadership (k = 5), Staffing adequacy (k = 11), Participation in decision-making (k = 0), Organizational culture (k = 5), Nurse autonomy (k = 3), Global (k = 0), Recognition (k = 1), Clarity of roles and goals (k = 5), Salary (k = 1), Workplace safety (k = 1), Physical comfort (k = 5), Professional development opportunities (k = 4), Innovation (k = 0), Flexible scheduling (k = 0)
Outcomes | Quality (k = 12); Safety (k = 16) | Quality (k = 7); Safety (k = 9)

Notes. Some studies were conducted in several countries, including non-OECD countries; thus, the total k across individual countries exceeds k of studies.

Abbreviations. OECD=Organisation for Economic Cooperation Development countries.

Across the KQ1 analytic^38–74^ and non-analytic studies,^8,75–137^ all of the workplace factors were measured by at least 1 study (Figure 1). Teamwork was the most frequently reported workplace factor (k = 46 KQ1a; 19 KQ1b). Staffing adequacy (k = 43 KQ1a; 16 KQ1b) and leadership (k = 41 KQ1a; 17 KQ1b) were a close second and third most frequently reported workplace factors. The rest of the 14 workplace factors were less frequently reported. The factor that appeared the least in the identified literature was salary (k = 2).

Figure 1 Workplace Factors Identified Across Included KQ1a and KQ1b Studies

Notes. Shows workplace factors identified in both the analytic and non-analytic studies.

All 14 workplace factors and the global factor are shown in the bar chart along the x axis. The y axis shows the frequency that each factor appears in the literature identified in KQ1a and KQ1b as two separate bars for each factor. Reported factors are: Teamwork (KQ1a 46, KQ1b 19), Leadership (KQ1a 41, KQ1b 17), Staffing adequacy(KQ1a 43, KQ1b 16), Participation in decision making (KQ1a 17, KQ1b 5), Salary (KQ1a 1, KQ1b 0), Organizational stability or culture (KQ1a 22, KQ1b 8), Global, Nurse autonomy (KQ1a 16, KQ1b 7), Recognition(KQ1a 5, KQ1b 2), Clarity of roles and goals(KQ1a 5, KQ1b 4), Workplace safety(KQ1a 10, KQ1b 5), Physical comfort (KQ1a 10, KQ1b 9), Professional development (KQ1a 13, KQ1b 6), Innovation(KQ1a 8, KQ1b 2), Flexible scheduling(KQ1a 5, KQ1b 3)

## KEY QUESTION 1A WHAT IS THE IMPACT OF NURSE WORK ENVIRONMENT CHARACTERISTICS ON NURSE-RATED HEALTH CARE QUALITY AND SAFETY?

### Global Nurse Work Environment

Six studies contributed data to assessment of global workplace factors, defined as measures encompassing 2 or more nurse work environment domains.^38,48,53,54,59,61^ Of these, 5 explored associations with health care quality (4 fair ROB^38,48,54,61^; 1 poor ROB^59^) and 3 assessed patient safety (3 fair ROB^53,54,61^; 0 poor ROB). The most common ROB limitations included cross-sectional design, use of unvalidated measures, low or unclear response rates, and insufficient methodological detail. Overall, summary estimates showed a positive association between work environment and nurse-rated health care quality and patient safety.

#### Quality

Of the 5 studies that assessed health care quality, all demonstrated a positive trend (Figure 2). Pooled analysis of 15,427 nurses demonstrated a medium association between global measures of workplace environment factors and nurse-reported health care quality (SRW = 0.39, 95% CI [ 0.09, 0.68]), indicating that supportive work environments contribute to improved perceptions of quality of care by nurses. Yet effect estimates were generally inconsistent across studies (95% prediction interval [PI] [−0.32, 1.10]). Heterogeneity between study effects may be attributable to variation in measurement tools for the work environment. For example, 2 studies used measures derived from or based on the PES-NWI^38,54^ and used 7 items across 4 domains^38^ or 5 subscales with 29 items of the Australian version of the Nursing Work Index-Revised (NWI-R).^59^ Other studies utilized a 5-subscale, 18-item adaptation of the Health Work Environment Assessment Tool (HWEAT)^61^ or 30 items across 6 subscales from the Team Effectiveness Scale for Nursing Units (TES-NU).^48^ Measures of quality included an author-developed single question regarding perceptions of quality of care,^54^ and previously validated similar single items about quality of care.^38,48,59,61^

Figure 2 Global Nurse Work Environment and Nurse-Rated Health Care Quality

Forest plot of global nurse work environment and healthcare quality. Overall standardized regression weight (0.39) shows a positive association between global work environment and healthcare safety. The pooled analysis is significant (95% CI 0.09 to 0.68), though there is substantial heterogeneity across studies (95% PI −0.32 to 1.10).

#### Safety

Of the 3 studies that assessed patient safety, all reported positive associations with some metric of overall nurse work environment. Pooled analysis of 9,099 nurses showed a positive and medium association between global measures of workplace environment factors and nurse-reported patient safety (SRW = 0.42, 95% CI [0.13, 0.71]). Yet effect estimates varied widely across included studies, as suggested by the 95% PI (−0.14, 0.98) (Figure 3). As above, heterogeneity in effect estimates across studies may be attributed to the various measures used to assess a global nurse work environment. The 3 studies that assessed perception of safety utilized HWEAT,^61^ the abbreviated PES-NWI,^54^ or 5 subscales that analyzed participation in hospital affairs, foundations for quality of care, manager ability and support, staffing and resource adequacy, and collegial relationships between nurses and physicians.^53^ Nurse-rated patient safety was measured using the Hospital Survey on Patient Safety Culture (HSOPSC) single item question.^53,54,61^

Figure 3 Global Workplace Factors and Nurse-Rated Patient Safety

Forest plot of global nurse work environment and healthcare safety. Overall standardized regression weight (0.42) shows a positive association between global work environment and healthcare quality. The pooled analysis is significant (95% CI 0.13 to 0.71), though there is substantial heterogeneity across studies (95% PI −0.14 to 0.98).

### Teamwork

Ten studies^39,40,43–45,48–50,59,62^ (7 fair ROB^39,40,43,44,48,50,62^; 3 poor ROB^45,49,59^) reported some measures of teamwork and its association with health care quality or patient safety outcomes. Overall sources of bias included cross-sectional study design, convenience sampling, no sample size or power justification, low response rate, lack of measure validation, and failure to adjust analysis for confounding variables. In summary, teamwork as a standalone work environment factor showed a slight positive, though not statistically significant, relationship with quality and a significant positive association with safety.

#### Quality

Four studies examined associations between work environment teamwork and quality of care.^39,45,48,59^ The study sample sizes ranged from 95 to 2,183 with a total sample of 3,143 nurses across all 4 studies. One study included the same measures among 3 subsamples, general wards, palliative care, and home care nurses, in Japan.^45^ The other 3 studies included nurse samples in critical care units (inpatient) in Belgium,^39^ acute care (inpatient) units in Korea,^48^ and mixed (inpatient and outpatient) units in small rural hospitals in Australia.^59^

There were 3 different measures of teamwork, including the collegial nurse-physician relations subscale from the Practice Environment Scale of the Nursing Work Index (PES-NWI),^39,59^ community or overall quality of social interactions at work from the Areas of Worklife Survey risk factors for burnout,^45^ and cohesion subscale from the Team Effectiveness Scale for Nursing Units (TES-NU).^48^ The measures of quality across these studies were all similar 1-item measures and included a previously established single question regarding nurse-rated quality of care,^3,17,79^ though 1 study specifically adapted the item to ask about quality of care at the end of life.^45^

Meta-analysis included 6 associations (Figure 4). Two of the 6 associations had statistically significant positive associations between teamwork and quality: community among palliative care nurses (OR = 2.872, 95% CI [0.022, 1.161], N = 128)^45^ and collegial nurse-physician relations (correlation r = 0.43, p < 0.01, N = 383).^59^ Notably, the latter study was the only one to use simple correlation analysis and no adjustments for covariates.^59^ In the meta-analysis, there was a small positive relationship between teamwork and quality, but this relationship was not statistically significant, and the 95% PI suggests a large amount of variability between studies (SRW = 0.15, 95% CI [−0.00, 0.31], 95% PI [−0.21, 0.52]).

Figure 4 Meta-Analysis of Associations Between Teamwork and Nurse-Rated Health Care Quality

Forest plot of teamwork and quality of care. Overall standardized regression weight (0.15) shows a positive association between teamwork and quality. The pooled analysis is not significant (95% CI −0.00 to 0.31), and there is substantial heterogeneity across studies (95% PI −0.21 to 0.52).

#### Safety

Seven studies reported on the association between nurse evaluations of teamwork and patient safety. The study sample sizes ranged from 170–34,514 with a total sample of 40,450 nurses across all 7 studies. The samples in these studies included nurses in critical care units in Belgium^39^ and mixed inpatient units in Austria,^40^ Canada,^62^ the United States,^43,50^ and Slovakia.^49^

There were 8 different measures of teamwork: (1) collegial nurse-physician relations^39^ subscale from the PES-NWI; (2) relational quality measured by the Leader-Member Exchange 7 questionnaire (LMX-7)^40^; (3–4) 2 individual items from the HSOPSC^43^; (5–7) the teamwork within units, teamwork across units, and handoffs and transitions subscales from the HSOPSC^44,49,50^; and (8) teamwork climate on unit subscale in the Safety Attitudes Questionnaire.^62^

Most of the measures of safety included a single question regarding overall patient safety grade from an uncited item,^39^ the HSOPSC.^43,49,62^ Three included subscale scores from the HSOPSC.^40,44,50^

The meta-analysis included 11 associations with a trend towards a positive relationship between teamwork and safety. Six of the 11 items had statistically significant positive associations between teamwork and safety. Notably, of the 5 associations that were not significant, 1 was focused on nurse-physician relations^39^ and the other 2 looked at teamwork across units,^49,50^ whereas the 8 that showed significant positive relationships all looked at teamwork within unit. Overall, the meta-analysis (Figure 5) indicates that as levels of teamwork increase, nurse-rated patient safety also increases (SRW = 0.14, 95% CI [0.07, 0.20]). The prediction interval (95% PI [−0.06, 0.33]) demonstrates high heterogeneity between studies, indicating that future studies could demonstrate a small negative or similar positive relationship between nurse perceptions of teamwork and safety.

One additional study measured multiple teamwork items and overall perceptions of safety from the HSOPSC and did not find a statistically significant association in their regression analysis.^44^ This study was not included in the meta-analysis, as it only reported statistical findings for significant results and therefore there was no coefficient to use for meta-analysis.

Figure 5 Meta-Analysis of Associations Between Teamwork and Nurse-Rated Patient Safety

Forest plot of teamwork and patient safety. Overall standardized regression weight (0.14) shows a positive association between teamwork and safety. The pooled analysis is significant (95% CI 0.07 to 0.33), though there is substantial heterogeneity across studies (95% PI −0.06 to 0.33).

### Leadership

Nine studies examined the work environment factor leadership and its impact on nurse-rated quality and/or safety. Across studies, the concept of leadership was operationalized in multiple ways. When assessing the contribution of leadership to nurse-rated care quality, the primary literature used measures of manager ability, leadership, and support of nurses^39,48,59^ to capture this work environment factor. When assessing the contribution of leadership to nurse-rated patient safety, measures included manager-level impact^39,44,49–51^ and extended to measures of leadership levels in the organizational structure beyond the immediate supervisor or manager. Three studies explored leadership in the context of hospital management or senior leadership.^50,51,62^ As a standalone work environment factor, leadership was not significantly associated with quality, but was significantly associated with patient safety.

#### Quality

Three studies (2 fair ROB^39,48^; 1 poor ROB^59^) explored leadership in the context of nurse-rated quality. All studies utilized a cross-sectional design with the number of enrolled participants in a single study spanning from 230 to 2,321.^39,48,59^ Overall sources of bias included low response rates, unclear adjustments for confounders, and a lack of psychometrics reporting for an author-developed tool that was not commonly used in this literature. The studies were conducted in distinct geographic locations, settings, and time periods. One study surveyed nurses working in Australian rural hospitals (mixed inpatient and outpatient) in 2018 using the Nursing Workforce Index-Revised: Australian (NWI-R:A).^59^ One study used the PES-NWI^39^ to study nurses employed across 75 intensive care units in Belgium from December 2021 to February 2022. Kim and Ko (2023) studied Korean acute care nurses using the Team-Effectiveness Scale for Nursing Units (TES-NU)^48^ across 3 general hospitals in January 2023 with units providing either general or integrated care. In all 3 studies, quality of nursing care was measured using similar single-item questions,^17^ with respondents asked to rate the quality of nursing care delivered to patients.

One study had the largest sample of nurses that provided data for analysis (N = 2,183).^39^ That study reported findings as not significant for a relationship between the manager’s ability, leadership, and support subscale of the PES-NWI and nurse-rated good or excellent quality of care (OR = 0.98 [0.87, 1.09]). Another study had the smallest sample size of this group of studies (N = 230).^48^ While they reported that there was a statistically significant positive correlation (r = 0.43, p < 0.001) between nursing leadership (described as leadership of the head nurse) and nurse-rated quality of care, the statistical significance did not remain in the authors’ regression model (SRW = 0.12) where other structure and process variables were included. The last study (N = 383) found that the nurse manager ability, leadership, and support of nurses subscale of the NWI-R:A identified a significant positive correlation (r = 0.44, p < 0.01) between leadership and nurse-rated quality of care.^59^

The meta-analysis across the 3 studies (N = 2,796 nurses) demonstrates high variability between this small number of studies; the SRW with 95% CI for all studies is 0.18 [−0.40, 0.76] (see Figure 6), which crosses the line of null effect. Pooled results suggest that there is potentially a small positive, though not a statistically significant relationship. Because the prediction interval is very large, ranging from a strong inverse association to a strong positive association (95% PI [−0.96, 1.33]), there is evidence of large heterogeneity between these included studies.

Figure 6 Meta-Analysis of Associations Between Leadership and Nurse-Rated Health Care Quality

Forest plot of leadership and quality of care. Overall standardized regression weight (0.18) shows a positive association. The pooled analysis is not significant (95% CI −0.40 to 0.76), and there is substantial heterogeneity across studies (95% PI −0.96 to 1.33).

#### Safety

Seven studies (5 fair ROB^39,44,50,51,62^; 2 poor ROB^49,52^) explored the impact of leadership on nurse-rated patient safety. ROB sources for these studies included low response rates, cross-sectional design, convenience sampling, low reliability coefficients for workplace measure in the Slovak version of the HSOPSC, study objectives not clearly stated, and measures not well described, defined, or cited. The number of participants that contributed to the studies spanned from 170 to 34,514. The studies were conducted in a variety of countries. One study was conducted in Belgium,^39^ 2 studies were in the US,^50,51^ 2 studies originated in Slovakia,^44,49^ 1 study was conducted in Poland,^52^ and 1 study was conducted in Canada.^62^ There was also a diversity in settings for these studies. One study reported an ICU only setting,^39^ 1 study reported on only surgical settings,^51^ while other settings reported in our sample included general medicine, internal medicine, mental health, emergency department, surgical care areas or departments, mixed inpatient, and combination medical/surgical units.^44,49,50,52,62^ The most common instruments that were used to assess the relationship between leadership and nurse perception of patient safety were the HSOPSC and PES-NWI.

Across the analyzed studies, there were 5 different measures of leadership including: (1) manager ability, leadership, and support subscale of the PES-NWI^39^; (2) support for nurses from management subscale of the PES-NWI^52^; (3) the senior leadership and supervisory leadership subscales of the Canadian Patient Safety Climate Survey (Can-PSCS)^62^; (4) the supervisor/manager expectations and actions promoting safety subscale of the HSOPSC^44,49–51^; and (5) the feedback and communication about error subscale of the HSOPSC.^44,49–51^

Most of the studies used the single question from the HSOPSC to measure nurse-rated patient safety.^49,51,62^ Two studies opted to use the perception of patient safety subscale of the HSOPSC.^44,50^ Two studies used questions similar to the HSOPSC single item question with Likert scale response options.^39,52^

The meta-analysis across the 7 studies (N = 53,042) demonstrates the effect of a relatively small number of studies and conflicting outcomes among those studies that investigated the relationship between leadership and nurse-perception of patient safety. The SRW with 95% CI for all studies is 0.12 (0.03, 0.22) (see Figure 7). The combined results suggest a potential statistically significant relationship. Yet because the prediction interval is wide (95% PI [−0.19, 0.43]), there is evidence of large heterogeneity across these included studies.

Figure 7 Meta-Analysis of Associations Between Leadership and Nurse-Rated Patient Safety

Forest plot of leadership and patient safety. Overall standardized regression weight (0.12) shows a positive association. The pooled analysis is significant (95% CI 0.03 to 0.22), though there is substantial heterogeneity across studies (95% PI −0.19 to 0.43).

### Nurse Autonomy

Two studies,^45,52^ both poor ROB, measured the association of nurse autonomy and nurse-rated health care quality (k = 1)^45,52^ and patient safety outcomes (k = 1).^52^ Overall sources of bias included cross-sectional study design, differences in response rate by setting potentially impacted by the COVID-19 pandemic, unclear study aim, unclear work environment measures, and rapid peer review timeline. There was no significant association with nurse autonomy and quality in the 1 study identified for analysis. One study reported safety as an outcome and reported a likely positive trend with nurse autonomy.

#### Quality

One study of 317 nurses used the Areas of Worklife Survey to evaluate the extent to which nurses across three settings (ie, general wards, palliative care units, home care agencies) reported they were able to make important decisions about their work.^45^ Quality of care was assessed using established single question with a 4-point scale^17^ adapted specifically for end-of-life care, and results were reported by nursing care setting. Across these settings, there were no significant associations between nurse perceptions of autonomy at the workplace and nurse-rated health care quality. The odds of reporting higher quality in the general ward were lower among those reporting workplace control (OR = 0.545), whereas the odds of better quality were greater among those reporting workplace control in the palliative care setting (OR = 1.013) and home care setting (OR = 1.047). Response rates were lowest within the general ward compared (24.4%) to the other 2 settings (palliative care = 50%, home care = 66.7%).

#### Safety

One study^52^ (poor ROB) of 1,796 nurses reported on the relationship between autonomy and nurse-rated patient safety. The author-developed survey asked nurses to rate their satisfaction with independence at work using a 4-point scale. Responses were recategorized as unsatisfied (ie, combining very unsatisfied and a little unsatisfied), medium satisfied, and very satisfied. Nurse assessment of overall patient safety was evaluated using an author-developed 5-point scale grouped into 3 categories of low patient safety, medium patient safety, or high patient safety. There was a significant difference between these categories (p < 0.001). Within the high patient safety responders group, a higher percentage of nurses reported being very satisfied with the independence at work (22.1% very satisfied) compared to the low safety group (2.8 % very satisfied).

### Staffing Adequacy

Eleven studies (7 fair ROB^38,39,44,50,51,56^; 5 poor ROB^45,49,52,59,60^) reported measures of staffing adequacy associations with either health care quality or safety outcomes. Overall sources of bias include cross-sectional study design, low or unclear response rates, unclear workplace measures, multiple analysis of the same phenomena, and unclear adjustments for confounders. Meta-analysis demonstrated that staffing adequacy was positively and significantly associated with both quality and safety.

#### Quality

Five studies evaluated associations between staffing adequacy and quality of patient care.^38,39,45,56,59^ The studies ranged from 95 nurses to 6,643 nurses, with 10,477 in total. One study surveyed critical care nurses,^39^ 2 surveyed mixed inpatient nurses,^45,56^ and 2 surveyed mixed inpatient and outpatient nurses.^38,59^ There were 4 different measures of staffing adequacy used: staffing and resource adequacy subscale of the PES-NWI^39,59^ or a single item,^38^ Areas of Worklife Survey,^45^ and an author-developed single-item question on hours of overtime worked per week.^56^

Two studies measured nurse-rated quality using the HSOPSC single-item measure of overall quality of care.^38,56^ Two studies used adapted versions of the previously established single-question quality of care question.^17^ One study adapted the question for patients whose death within a year would not be surprising^45^ and another for international health care settings.^59^ One study used a similar, uncited single question describing the quality of care delivered to patients.^39^

The meta-analysis shows 7 analyses across the 5 studies (Figure 8). Three of the associations had statistically significant positive associations: staffing adequacy,^31^ general ward workload,^45^ and staffing and resource adequacy.^59^ The overall association was modest but significant (SRW = 0.18, 95% CI [0.04, 0.33]), though the 95% PI (−0.20, 0.57) demonstrates a very large amount of heterogeneity between studies.

Figure 8 Meta-Analysis of Associations Between Staffing Adequacy and Nurse-Rated Health Care Quality

Forest plot of staffing adequacy and quality of care. Overall standardized regression weight (0.19) shows a positive association. The pooled analysis is significant (95% CI 0.07 to 0.30), though there is substantial heterogeneity across studies (95% PI −0.15 to 0.52).

#### Safety

Eight studies evaluated associations between staffing adequacy and patient safety. The studies ranged from 104 nurses to 34,514 nurses, with 53,906 in total. One study surveyed nurses in critical care settings^39^ and 1 in procedural inpatient settings.^51^ Five studies surveyed mixed inpatient nurses,^44,49,50,52,56^ and 1 surveyed mixed inpatient and outpatient nurses.^60^ There were 4 different established measures of staffing adequacy used: PES-NWI on staffing adequacy,^39,52^ HSOPSC on staffing adequacy,^44,49–51^ Individual Workload Perception Scale,^60^ and multiple items on care left undone.^60^ Two studies used single-item measures: hours of overtime worked^56^ and reported nurse-to-patient ratios.^60^ Six studies assessed nurse-rated patient safety using either the single item^49,51,56,60^ from the HSOPSC or the subscale.^44,50^ One study used an author-developed survey of nurses’ assessment of overall patient safety with a 5-point scale grouped into 3 categories of low, medium, or high patient safety.^52^

The meta-analysis shows 10 analyses across the 8 studies (Figure 9). Five of the associations had statistically significant positive associations: staffing adequacy,^44,50,51^ staffing and resource adequacy,^52^ and nurse care left undone.^60^ The overall association was modest but significant (SRW = 0.17, 95% CI [0.09, 0.24]), though the 95% PI (−0.06, 0.39) demonstrates a very large amount of heterogeneity between studies.

Figure 9 Meta-Analysis of Associations Between Staffing Adequacy and Nurse-Rated Patient Safety

Forest plot of staffing adequacy and patient safety. Overall standardized regression weight (0.17) shows a positive association. The pooled analysis is significant (95% CI 0.09 to 0.24), though there is substantial heterogeneity across studies (95% PI −0.06 to 0.39).

### Clarity of Roles and Goals

Our analytic dataset did not include studies that assessed the impact of the work environment factor of clarity of roles and goals.

### Recognition

Only 1 study (poor ROB) reported recognition as it relates to perceptions of quality.^45^ Overall sources of bias included differences in response rate by setting and external factors impacting data collection.

#### Quality

One study of 347 nurses across 3 different care environments (95 in general wards, 128 in palliative care units, and 124 in home care settings) sought to explore factors associated with nurses’ perceptions of reward as a proxy for recognition and end-of-life care quality.^45^ The established Areas of Worklife Survey was used to measure reward using a subscale about financial and social recognition for job contributions. Nurse-rated quality was assessed using an established single question^17^ adapted for patients whose death within a year would not be surprising. Responses surrounding end-of-life care were rated on a 4-point scale ranging from poor to very good. The study reported mixed findings, with odds ratios ranging from 0.36 to 0.79 across the 3 care settings (total range of 95% CIs [0.11, 2.53]). None of the estimates were statistically significant, and the wide range of confidence intervals may be impacted by the small number of nurses surveyed within each setting.

#### Safety

None of the studies in the analytic dataset reported recognition as it relates to nurses’ perceptions of safety.

### Physical Comfort

Only 1 study (fair ROB) reported physical comfort and nurse-rated patient safety.^55^ For the purpose of this report, nurse work environment physical comfort included availability and adequacy of equipment, materials, technological tools, supplies, and other non-human resources. Overall sources of bias included cross-sectional study design and unclear blinding of outcomes assessment.

#### Quality

None of the studies included in this analysis reported physical comfort and nurse-rated quality.

#### Safety

One study of 398 inpatient nurses reported nurses’ views of the electronic health record (EHR).^55^ Authors used a validated 14-item survey to measure EHR use, quality, and satisfaction. The patient safety outcome was measured using the Patient Safety Culture Questionnaire. The regression weights showed a small positive correlation between use (0.2, [p < 0 .01]), quality (0.13, [p < 0.05]), and satisfaction (0.286, [p > 0 .01]) and nurse perceptions of patient safety.

### Flexible Scheduling

Two studies (1 fair ROB^46^; 1 poor ROB^52^) reported some measures of flexible scheduling and its association with health care quality or patient safety outcomes. Overall sources of bias included cross-sectional study design, unclear study aim, unclear work environment measures, and rapid peer review timeline.

#### Quality

One study of 1,164 inpatient nurses reported flexible scheduling defined as either routine shift (ie, 8 hours), long shift (ie, 12 hours), or other shift arrangements and nurse-rated quality.^46^ Nurse-rated health care quality, as well as shift type, were collected using items from the Perceived Implicit Rationing of Nursing Care (PIRNCA) tool. In a multivariate regression, long shift length was negatively associated, though not significant, with nurses’ assessment of patient care quality compared to routine shift length (regression coefficient = −0.28, 95% CI [−0.729, 1.131]). Similarly non-significant, other shift types were positively associated with care quality (regression coefficient = 0.169, 95% CI [−0.792, 1.131]) compared with routine shift.

#### Safety

One study of 1,796 inpatient nurses reported on the association between nurse perceptions of flexible scheduling and nurse-rated patient safety.^52^ The author-developed study survey asked nurses to rate their satisfaction with the flexibility of their work schedule using a 4-point scale ranging from unsatisfied to very satisfied. Nurses’ assessment of overall patient safety was evaluated using a 5-point scale grouped into 3 categories of low, medium, or high patient safety. There was a significant difference reported between these categories (p < 0.001). Although no effect estimate was reported, among the nurses who assessed patient safety to be high, more were satisfied with the flexibility of the work schedule (29.4%) compared to those who reported being unsatisfied (14.7%). Those who reported low patient safety demonstrated less satisfaction with flexibility (48.7%) compared to those in the very satisfied category (7.4%).

### Organizational Culture

Nine cross-sectional studies (7 fair ROB^41,43,44,50,51,57,58^; 2 poor ROB^45,49^) reported associations between organizational culture and health care quality (3 studies)^45,57,58^ or patient safety (7 studies).^41,43,44,49–51,57^ These studies included a total of 23 associations between organizational culture measures and health care quality (9 analyses^45,57,58^) or patient safety (14 analyses). We define organizational culture as the social conditions and norms among nurses in the workplace not explicitly linked to any other environmental factors. Some of these organizational culture-related measures in our review include psychological safety (ie, a comprehensive measure of how safe team members feel sharing opinions, admitting mistakes, and challenging the status quo), standards around non-punitive responses to errors, communication openness, and the extent to which nurses felt like they could speak up when they see something wrong. Meta-analysis demonstrated a non-significant positive association between organization culture and quality and a small positive, significant relationship with safety.

#### Quality

Three studies measured associations between organizational culture and health care quality, encompassing a total of 9 analyses.^45,57,58^ Study samples ranged from 95 to 729, with a total of 1,486 nurses across the studies. One^45^ study considered 2 aspects of organizational culture (fairness and values) across general ward, palliative, and home care settings. Notably, each of the 6 analyses include the null in their confidence intervals, which suggests that there is no association between fairness or values across each of these analyses. However, it should be noted that this lack of a significant association may be due to the small sample size (general ward N = 95, palliative care N = 128, home care N = 124) and inherent lack of power in the study arms. When considering studies with greater sample sizes, we observe a clearer positive association between communication-related organizational culture factors and patient care quality. While the association between destructive listening and quality of care is not significant (95% CI [−0.06, 0.18]), the associations of quality with speaking up climate or constructive listening are significant.

The meta-analysis across all 3 studies shows that as the perception of organizational culture reflects more positive sentiments, nurse ratings of patient care quality increase as well (SRW = 0.11, 95% CI [0.00, 0.22]) (Figure 10). Although the confidence interval includes the null, these findings are suggestive of a positive association. However, the wide prediction interval (95% PI [−0.14, 0.37]) suggests that there is high heterogeneity among the organizational culture measures across studies. Notably, all 3 studies included care provided for mixed inpatient and outpatient populations. Some sources for heterogeneity are that 1 study (which accounted for 2 associations considered in this forest plot) examined the treatment quality of violent patients,^58^ while others emphasized end-of-life quality of care or employed a previously established singular question assessing overall care quality.^4,17^ Simply, most studies included in this meta-analysis asked about quality of care within specific care contexts (eg, among violent or end-of-life patients) that may not be comparable to each other due to exogenous patient-specific factors. Due to the apparent heterogeneity of findings across studies, our findings suggest that there is broad variation in how nurses in these studies conceptualize quality of care.

Figure 10 Meta-Analysis of Associations Between Organizational Culture and Nurse-Rated Health Care Quality

Forest plot of organizational stability or culture and healthcare quality. Overall standardized regression weight (0.11) shows a positive association. The pooled analysis is not significant (95% CI 0.00 to 0.22), though there is substantial heterogeneity across studies (95% PI −0.14 to 0.37).

#### Safety

Seven studies examined how 14 organizational culture measures were associated with nurse-rated patient safety.^41,43,44,49–51,57^ Study samples ranged from 195 to 34,514, with a total of 51,170 nurses across the studies. The meta-analysis across all 7 studies shows that as the perception of positive organizational culture factors increase, ratings of patient safety increase as well (SRW = 0.14, 95% CI [0.10, 0.19]) (Figure 11). This SRW confidence interval does not encompass the null value and strongly suggests a positive association between organizational culture and perceptions of patient safety. Yet the prediction interval (PI [−0.02, 0.31]) overlaps the null and suggests some heterogeneity.

Of the 14 organizational culture analyses included in this forest plot, clear positive associations with patient safety were observed for 10 analyses. Five studies examined nurses providing care for mixed (inpatient) patient populations, while the remaining 2 studies focused on nurses providing care for procedural unit (inpatient) and acute care unit (inpatient) populations, respectively. All 4 non-significant organizational culture measures belonged to the HSOPSC^49,51^ and emerged as significant predictors of patient safety in other studies similarly operationalizing those same factors.^41,44,50^ Notably, 3 of the 4 organizational culture measures that did not demonstrate a significant association with patient safety belonged to a singular study, which had the smallest sample size relative to others.^49^ The lack of significant associations may be attributed to a lack of power in that 1 study. Alternatively, 2 of the 4 non-significant associations employed the non-punitive response to error exposure HSOPSC subscale: once in a small sample of Slovak nurses providing internal medicine or surgical care (N = 195),^49^ and again in a much larger sample of US nurses providing surgical specialty care (N = 12,715).^51^ The singular study wherein a significant association emerged had a relatively larger study sample (N = 34,514),^50^ and encompassed US nurses providing care in medical and surgical specialties. The differences across studies using the same organizational culture measure indicate that future studies may need to have larger sample sizes to observe any significant associations between non-punitive response to error and patient safety.

Figure 11 Meta-Analysis of Associations Between Organizational Culture and Nurse-Rated Patient Safety

Forest plot of organizational stability or culture and patient safety. Overall standardized regression weight (0.14) shows a positive association. The pooled analysis is significant (95% CI 0.10 to 0.19), though there is substantial heterogeneity across studies (95% PI −0.02 to 0.31).

### Professional Development Opportunities

Two studies (2 poor ROB) assessed the association between nurse-rated professional development and patient safety and quality.^42,52^ One study reported associations with quality,^42^ and 1 study reported associations with safety.^52^ The overall sources of bias included cross-sectional study design, unclear study population and response rate, and unclear measures of the work environment.

#### Quality

A study of mixed inpatient and outpatient nurses reported a significant positive association between professional development and nurse-rated patient care quality.^42^ This study (N = 350 nurses) used an author-developed tool to measure participation in quality improvement activities like audits, service evaluation, individual projects or research, presentations for conferences, or published literature as a proxy for engagement in professional development. The authors used an uncited single Likert scale question to measure how highly respondents perceive the quality of patient care at their current workplace. Nurses who engaged in professional development opportunities reported higher quality of patient care compared to nurses who did not (p < 0.01).

#### Safety

One study reported a significant difference between categories of professional development and nurse-rated patient safety (p < 0.001).^52^ This study of mixed inpatient nurses (N = 1,780) used an author-developed single item scale to measure the possibility of promotion as a proxy for professional development opportunities using 3 response options (unsatisfied, medium satisfied, and very satisfied). Overall patient safety was evaluated using an author-developed 5-point scale grouped into 3 categories of low patient safety, medium patient safety, or high patient safety. Within the high patient safety responders’ group, a higher percentage of nurses reported being very satisfied with professional development (9.7% very satisfied) compared to the low safety group (2.0% very satisfied).

### Salary

One study (poor ROB) reported satisfaction with salary as a workplace factor and nurse perception of patient safety.^52^

#### Quality

None of the studies identified reported associations between salary and perceptions of quality.

#### Safety

A study of mixed inpatient nurses (N = 1,789) used an author-developed scale to measure satisfaction with remuneration across 3 categories (very satisfied, medium satisfied, and unsatisfied) as well as an author-developed scale with 5-point response scale grouped into 3 categories of low patient safety, medium patient safety, or high patient safety.^52^ Within the high patient safety responders group, a higher percentage of nurses reported being very satisfied with remuneration (8.0% very satisfied) compared to the low safety groups (2.8% very satisfied). Authors reported a significant difference between categories (p < 0.001).

### Participation in Decision-Making

Three studies reported (1 fair ROB^39^, 2 poor ROB^52,59^) nurse perspectives on participation in decision-making and rating of care quality and safety. Overall sources of bias included cross-sectional study design, low response rates, and multiple workplace factors and outcome analyses. In narrative synthesis, nurse participation in decision-making was shown to be positively correlated with quality and exhibited a mixed association with safety.

#### Quality

Two studies of 2,183^39^ and 383^59^ nurses from mixed inpatient and outpatient settings measured the association between participation in decision-making and quality of patient care. Both studies used similar tools to measure workplace factors: 1 used the PES-NWI tool^39^ and the other used the Australian adaptation of the PES-NWI (NWI-R: A)^59^. Quality of patient care was measured using a single item adapted from the HSOPSC tool for international health care settings with a 4-point Likert response scale ranging from poor to excellent.^59^ Authors reported a significant positive correlation between quality of care and participation in hospital affairs (r = 0.48, [p < 0.01]).^59^ The other study used an uncited single question for the quality of nursing care delivered to patients with responses ranging from poor to excellent. This study showed a non-significant odds ratio for reporting good or excellent quality (OR = 0.89, 95% CI [0.78, 1.03]) among those who reported higher participation in hospital affairs.^39^

#### Safety

Two studies of 2,183^39^ and 1,825^52^ inpatient nurses reported participation in decision-making and safety. Both studies used the PES-NWI tool to measure nurses’ participation in hospital management or hospital affairs. One study used an author-developed single-item rating overall safety with 5 possible answers ranging from unsatisfactory to excellent. These responses were grouped into 3 categories: low, medium, and high patient safety. Within the high patient safety responders’ group, the median satisfaction with nurses’ participation in hospital management score was higher (2.71, interquartile range (IQR) [2.29, 3.0]) compared to those who responded with medium (median = 2.43, IQR [2.0, 2.86]) or low patient safety (median = 2, IQR [1.43 – 2.43]). There was a significant difference reported between these categories (p < 0.001).^52^ The other study used an uncited single item for overall patient safety grade with responses ranging from failing to excellent.^39^ The odds of acceptable, very good, or excellent patient safety (OR = 0.96, 95% CI [0.76, 1.22]) was lower among those who reported higher participation in hospital affaires.

### Innovation

Four cross-sectional studies (3 fair ROB^44,50,51^; 1 poor ROB^49^) assessed the association between nurse ratings of workplace innovation and patient safety. Overall sources of bias included cross-sectional design, unclear response rates, and unreliable exposure and unclear outcome measures.

#### Quality

None of the identified studies evaluated workplace innovation and nurse-rated health care quality.

#### Safety

All 4 studies that measured associations between workplace innovation and nurse-rated patient safety demonstrated a positive trend.^44,49–51^ These studies of inpatient nurse work environments used the organizational learning and continuous improvement subscale measure from the HSOPSC, which we used as a proxy for workplace innovation, and either the 1-item safety measure^49,51^ or the 4-item safety subscale from the same tool.^44,50^

The meta-analysis across all 4 studies (N = 4,8851 nurses) shows that as perceptions of workplace innovation increase, nurse ratings of patient safety also increase (SRW = 0.19, 95% CI [0.10, 0.27]) (Figure 12). The prediction interval (95% PI [0.05, 0.33]) demonstrates some heterogeneity between studies. Future studies are likely to also demonstrate a similar positive relationship between nurse perceptions of innovative work environments and nurse-rated patient safety.

Figure 12 Meta-Analysis of Associations Between Innovation and Nurse-Rated Patient Safety

Forest plot of innovation and healthcare quality. Overall standardized regression weight (0.19) shows a positive association. The pooled analysis is significant (95% CI 0.10 to 0.27), with some heterogeneity across studies (95% PI 0.05 to 0.33).

### Workplace Safety and Violence

Three studies (3 fair ROB) measured the association between workplace safety and violence and either health care quality or patient safety outcomes.^47,56,58^ Overall sources of bias included cross-sectional study design, unclear eligibility criteria, and unclear or low survey response rate. In narrative synthesis, workplace safety and violence demonstrated an inverse and significant association with quality in 2 studies and with patient safety in 2 studies.

#### Quality

Two studies of mixed inpatient nurses reported on associations between workplace safety and nurse-reported quality.^56,58^ One study of Israeli nurses (N = 759) measured nurse-experienced violence load using a scale of 9 items related to verbal and physical violence committed by patients.^58^ This study measured nurse perceptions of patient care quality with a tool specifically for patients with abusive behaviors using 6 items summarized by a mean overall score. Authors reported that fewer incidences of patient violence were associated with higher perceptions of quality (p = 0.025).

One study of nurses in Alabama (N = 943) measured nurse-reported workplace bullying using the Short Negative Acts Questionnaire, an established tool of 9 items with a 5-point Likert scale regarding work-related, person-related, and physically intimidating bullying behaviors.^56^ Quality of patient care was assessed using the established single question for rating the quality of care.^17^ The odds of reporting high patient care quality were lower among nurses experiencing workplace bullying compared to those who were not experiencing workplace bullying (OR = 0.28; p < 0.0001).

#### Safety

Two studies reported the associations between perceptions of nurse workplace safety and perceptions of patient care safety.^47,56^ Both studies used the HSOPSC overall patient safety grade single item to measure nurse perceptions of patient care safety.

One study (N = 1,781) of inpatient and outpatient nurses measured workplace safety using the Workplace Violence Scale developed at the medical center where the study was conducted.^47^ This scale included 3 items about physical or verbal violence committed by patients and verbal violence committed by visitors. Authors reported an inverse relationship between violence and safety in the workplace and patient safety (correlation coefficient = −0.18; p < 0.001).

One study of nurses in Alabama measured work-related, person-related, and physically intimidating bullying behaviors.^56^ The odds of reporting high patient care safety were lower among those who reported workplace bullying (OR = 0.36; p < 0.0001) compared with those who did not report workplace bullying.

### Certainty of Evidence (COE)

We conducted COE ratings for stakeholder-prioritized workplace factors identified across the analyzed studies for which there was adequate data (Tables 6A and 6B). Overall, our COE was downgraded to very low certainty for inconsistency and for ROB across studies. Specifically, in the 3 observational studies that reported leadership and quality, we determined that there was very low certainty of a small association downgraded for very serious inconsistencies, serious imprecision, and serious ROB. The 6 studies reporting staffing adequacy showed very low certainty for a small association with perceptions of quality and was downgraded for similar reasons with serious inconsistency and imprecision as well as serious ROB. Four observational studies evaluating teamwork were assessed as very low certainty for a small association with quality due to serious inconsistency, serious imprecision, and serious risk of bias.

The studies reporting patient care safety showed a similar pattern of low COE for a small association with leadership, staffing adequacy, and teamwork. Across the 8 studies reporting leadership, there were serious inconsistencies in the individual study SRWs as well as serious imprecision and risk of bias. The 8 studies reporting staffing adequacy were also low COE due to serious inconsistencies, imprecision, and risks of bias. These studies were, however, sufficiently direct and applicable to nursing in OECD countries and in- and outpatient settings. None of the analyzed studies reported nursing autonomy as a workplace factor.

Table 6A Summary of Available Evidence for KQ1a: Impact of Nurse Work Environment Characteristics on Nurse-Rated Health Care Quality

Studies (Participants) | Summary of Findings | Consistency | Precision | Limitations | Directness | Certainty of Evidence
3 observational studies; (2,796) | Leadership; SRW = 0.18, 95% CI [−0.40, 0.76] | Very serious inconsistency | Very serious imprecision | Cross-sectional study designs, small or unclear response rates | No serious indirectness | Very low certainty of a small association of leadership with perceptions of quality.
5 observational studies; (10,247) | Staffing adequacy; SRW = 0.19, 95% CI [0.07, 0.30] | Serious inconsistency | Serious imprecision | Cross-sectional study designs, small or unclear response rates | No serious indirectness | Very low certainty of a small association of staffing adequacy with perceptions of quality.
4 observational studies; (2,891) | Teamwork; SRW = 0.15, 95% CI [−0.00, 0.31] | Serious inconsistency | Very serious imprecision | Cross-sectional study designs, small or unclear response rates | No serious indirectness | Very low certainty of a small association of teamwork with perceptions of quality.
1 observational study | Nursing autonomy Insufficient data | | | | | Insufficient

Abbreviations. SRW=standardized regression weight.

Table 6B Summary of Available Evidence for KQ1a: Impact of Nurse Work Environment Characteristics on Nurse-Rated Health Care Safety

Studies (Participants) | Summary of Findings | Consistency | Precision | Limitations | Directness | Certainty of Evidence
8 observational studies; (54,101) | Leadership; SRW = 0.15, 95% CI [0.07, 0.24] | Serious inconsistency and for leadership, staffing adequacy and teamwork | No serious imprecision | Cross-sectional study designs, small or unclear response rates | No serious indirectness | Very low certainty of a small association of workplace factors with perceptions of quality.
8 observational studies; (53,906) | Staffing adequacy; SRW = 0.17, 95% CI [0.09. 0.24] | Serious inconsistency | No serious imprecision | Cross-sectional study designs, small or unclear response rates | No serious indirectness | Very low certainty of a small association of workplace factors with perceptions of quality.
7 observational studies; (40,450) | Teamwork; SRW = 0.14, 95% CI [0.07, 0.20] | Serious inconsistency | No serious imprecision | Cross-sectional study designs, small or unclear response rates | No serious indirectness | Very low certainty of a small association of workplace factors with perceptions of quality.
1 observational study | Nursing autonomy Insufficient data | | | | | Insufficient

Abbreviations. SRW=standardized regression weight.

## KEY QUESTION 1B HOW DO NURSES PERCEIVE THAT THEIR WORK ENVIRONMENT IMPACTS HEALTH CARE QUALITY AND SAFETY?

### Teamwork

We defined teamwork as encompassing positive work relationships among the nurses or other personnel, interprofessional relations, peer cohesion, social support, collaborative decision-making, and the amount of clinical support.^16^ The team was determined to include the health care providers (eg, all levels of nurses, physicians, therapists, etc) as well as patients and/or families.

#### Quality

We identified 3 themes within the teamwork domain for quality across 7 studies (Table 7).^65,67,69,71–74^ The first theme in this domain was related to the skills required for functioning as a team. This theme was noted in 5 studies.^65,71–74^ The first subtheme is communication as a skill, which was noted in 4 studies.^65,71–73^ This subtheme stressed the importance of sending and receiving a clear message; when this did not happen, there were negative consequences for patient care. This may be in the form of different messages from team members to the patient^71^ creating confusion for the patient. These negative communications can also lead to unclear job descriptions and scheduling challenges.^73^ The second subtheme of team processes or the skills used to engage in teamwork was noted in 4 studies.^65,71,73,74^ Some of the other skills used within the teams included collaboration^65,73^ and delegation of tasks.^74^ The second theme was team relationships, which described the impact of team interactions or dynamics on quality. This theme was noted in 5 articles.^67,69,72–74^ The majority of the articles focused on the positive aspects of interactions where the teams worked as a unit, leading to the subtheme of team cohesion.^69,72–74^ The studies described how positive team interactions could help them cope with stress and work more efficiently.^74^ Another study went on to describe how the nurses felt it was their professional responsibility to work collectively.^73^ Not all of the team interactions were positive, leading to the subtheme of team tension. For example, there was 1 article that described how negative interactions of the team, such as disagreements, were associated with new graduate nurses being less committed to patient care.^67^ The third theme was selecting focus, which describes when priorities shift from the needs of 1 team member to another. This was highlighted in 1 article.^67^ Examples included when a student nurse interrupted a nurse, so a patient’s feeding was paused.^67^ Another example described frequently in this article was the prioritization of gathering data for physician rounds rather than providing direct patient care.^67^

Table 7 Themes of Teamwork and Quality

Theme | Definition | Exemplar Quotes
Teamwork Skills ^65^ ^,^ ^71–74^ | Defined as the techniques required by nurses to successfully practice with a health care team to deliver safe and effective care.; [underlined: Subthemes]; Team Communication: Defined as the ways in which team members (including patients and families) exchange information in the course of their duties impacting quality and safety.; Team Processes: Defined as team practices or skills other than communication, which are used to facilitate teamwork impacting quality and safety. | Positive quote: “…quality care should be well coordinated…to have meaningful communication with doctors…so to be able to provide holistic and meaningful care”^73^; Negative quote: “’miscommunication with other professionals, shift schedules and unclear job description…these have a negative impact on care”^73^; Team Processes:; Positive quotes: “Nurses slightly more often mentioned interpersonal factors (n = 32/48; 67%). Particularly, they raised ‘team collaboration,’ ‘good medical-nursing collaboration,’ ‘involvement of interpreters,’ and ‘a relationship of trust’ as indicators of good interpersonal care processes.”^65^
Team Relationships ^67^ ^,^ ^69^ ^,^ ^72–74^ | Defined as the ways in which team members interact with one another and their influence on patient safety and quality.; [underlined: Subthemes]; Team Cohesion: Defined as the ways in which the team works together including supporting one another impacting quality and safety (includes collaboration).; Team Tension:; Defined as the ways in which the team engages in conflict or experiences negative reactions from others on the team impacting quality and safety. | Positive quote: “…it’s our personal duty to build a strong, solid cooperation between all these people (the health professionals). To be an unbreakable chain, so nothing could harm our good work, our care…”^73^; Team Cohesion:; Positive quotes “I do find…if I need help with anything, there’s not one staff [member] that would say no to helping or ‘explaining something to me.’”^69^; Team Tension:; Negative quote: “The way staff members sometimes communicated with each other reflected conflicting attitudes and disagreements on care priorities for how and when to respond patients’ care needs. As a result of this negative behaviour among staff, the newly graduated nurses became less committed (eg, not focusing on the patient being cared for) when delivering direct care.”^67^
Selecting Focus ^67^ | Defined as the nurse’s choice in what to attend to when aiming to deliver safe, quality care influenced by needs or priorities of another team member. | Negative quote: “In the ward, I [observer] ask her [nurse] why she prioritizes the round rather than meeting the patient’s need for care. I noted that she had checked and confirmed that she [the patient] had faeces in her diaper. She replies: ‘I know it’s poor care, but if I don’t do rounds now, it will have major consequences for me later where I must do the documentation.’”^67^

#### Safety

We identified 2 themes within the teamwork domain for safety across 4 studies (Table 8).^64,66,68,70^ The first theme that influenced patient safety was teamwork skills. Among the skills described, communication was described in all 4 articles.^64,66,68,70^ There was an emphasis on the way nurses used language to communicate with others such as use of active versus passive terminology^70^ when addressing safety concerns. Additional teamwork processes or skills were identified in 3 studies.^64,66,70^ Some of the other skills identified included collaborating and building rapport.^66^ The second theme focused on the dynamics or interactions of the team. This theme was included in 4 studies.^64,66,68,70^ There were 2 subthemes focused on whether the interactions were more positive in nature leading to the team working in a cohesive or supportive fashion, compared to those teams where the members seemed to be in conflict with one another. Four studies^64,66,68,70^ described cohesive team interactions, while tense interactions were noted in 2 studies.^66,70^ For teams demonstrating the subtheme of team cohesion, there was a sense of the team members being very supportive or encouraging of one another, creating an atmosphere of protection.^70^ In contrast, some teams experienced a sense of conflict among the members, generating the subtheme of team tensions. For example, a team member could feel dismissed or shut down^66^ rather than feeling supported by having their ideas embraced.

Table 8 Themes of Teamwork and Safety

Theme | Definition | Exemplar Quotes
Teamwork Skills ^64^ ^,^ ^66^ ^,^ ^68^ ^,^ ^70^ | Defined as the techniques required by nurses to successfully practice with a health care team to deliver safe and effective care.; [underlined: Subthemes]; Team Communication: Defined as the ways in which team members (including patients and families) exchange information in the course of their duties impacting quality and safety.; Team Processes: Defined as team practices or skills other than communication, which are used to facilitate teamwork impacting quality and safety. | Positive quote: “The communication with healthcare assistants is good; we delegate work to them and…there is no problem.”^64^; Team Communication:; Negative quote: ”Though the nurses wrote substantially on communicating with each other for safety, listening to patients or the MDT was more constrained.”^70^; Team Processes; Positive quote: “Teamwork Participants described many attributes of teams and teamwork that were important to managing gaps, solving problems, getting the work done, and ensuring that patients received adequate care. These qualities included co-operation, communication, respect, rapport…”^66^
Team Relationships ^64^ ^,^ ^66^ ^,^ ^68^ ^,^ ^70^ | Defined as the ways in which team members interact with one another and their influence on patient safety and quality.; [underlined: Subthemes]; Team Cohesion: Defined as the ways in which the team works together including supporting one another impacting quality and safety (includes collaboration).; Team Tension:; Defined as the ways in which the team engages in conflict or experiences negative reactions from others on the team impacting quality and safety. | Positive quote: “It’s very much a team game. I mean it’s a spiral, you all depend on each other to get the work done.”^66^; Team Cohesion; Positive quote: “These discussions focused on their ways of working together that were important and meaningful to their capacity to keep patients safe. These nurses also spoke of their collective support for each other whilst expressing some isolation from the organisation.”^70^; Team Tension; Negative quote: “When nurses adopt this narrative, they fail to acknowledge that keeping patients safe moves across professions and within all health care teams.”^70^

### Leadership

Leadership was defined as the positive and negative characteristics of health care leadership that influence the nurse work environment. Leadership was inclusive of both supervisors at the clinic or unit level and at higher levels within the health care system (eg, hospital management).

#### Quality

We identified 3 themes within the leadership domain for quality across 3 studies (Table 9).^72–74^ The first theme, noted in all 3 studies, centered on the key role that support of nurse supervisors and other leadership plays both in producing a nurse work environment that has the resources needed to provide quality care and in setting the tone in the workplace.^72–74^ Nurses expressed that leadership support influenced the health care quality culture in both positive and negative ways. For example, nurses felt that their leaders could improve many aspects of their work environment such as staffing and resources, which facilitated the delivery of quality care.^73^ The head nurse was seen as a pivotal player on the leadership team who exerted control over nursing culture on the wards.^74^ Additionally, supportive leadership was viewed as a pivotal factor in successful practice change by setting the pace and anticipating sources of conflict.^73^ The second theme, leadership trust, was only present in 1 study and focused on the role that a trusting leadership style had on promoting health care quality at an organizational level; yet nurses stressed that the development of trust between staff and leadership was a process that took time.^73^ Nurses expressed that a trusting leadership style meant recognizing the skills and knowledge of nursing staff in providing high quality care. The last theme, leadership communication skills, was also only present in 1 study and underscored the role that leadership communication skills play in health care quality culture.^72^ Nurses expressed that when leadership had effective communication around staff expectations, this, in turn, fostered both teamwork and a culture of accountability via adherence to these expectations.

Table 9 Themes of Leadership and Quality

Theme | Definition | Exemplar Quotes
Leadership Support ^72–74^ | The impacts that leadership support has on 1) procurement of resources (eg, staff) and 2) setting a tone/culture for health care quality. | Positive quote: “Leaders need to encourage and reward quality even if it’s everyday staff.”^72^; Negative quote: “The shortage of staff and equipment could be resolved at a managerial level. Supportive management decisions will really help us a lot to do our work in a better way and to provide good care…”^73^
Leadership Trust ^73^ | The impact of trust between leadership and nursing staff on transforming the culture around health care quality. | Positive quote: “A trusting leadership was referred to as a crucial organizational feature for introducing quality transformation at an organizational level. However, nurses stressed that this does not occur automatically but is a long-term process.”^73^
Leadership Communication Skills ^72^ | The role of leaderships’ communication skills in fostering the workplace culture of quality. | Positive quote:; “Communication/collaboration also related to Leadership—specifically, leaders’ expectations of their staff, how they convey these to their staff, and how well the leaders create a culture that promotes accountability and adherence to these expectations.”^72^

#### Safety

We identified 1 theme within the leadership domain for patient safety across 2 studies (Table 10).^64,68^ This theme focused on the impact of positive and negative leadership support on resource procurement and fostering a patient safety culture.^64,68^ For example, nurses perceived that a lack of support from hospital management for patient safety resulted in poor nursing work conditions such as staffing deficiencies, which, in turn, led to excessive overtime for existing staff.^64^ Positive leadership support was viewed as leadership that was dedicated to a culture of patient safety.^68^ Additionally, nurses perceived leaders to be competent if they expressed a clear focus and commitment to a patient safety culture.^68^

Table 10 Themes of Leadership and Safety

Theme | Definition | Exemplar Quotes
Leadership Support ^64^ ^,^ ^68^ | The impacts that leadership support has on 1) procurement of resources (eg, staff) and 2) setting a tone/culture for patient safety. | Positive quote: “Leadership being competent and committed, leadership being supportive, (has) a clear leadership focusing on safety.”^68^; Negative quote: “…nurses perceived a lack of support from hospital management resulting in poor work conditions including the lack of staff and excessive work pressure.”^64^

### Nurse Autonomy

Nurse autonomy was defined as perceptions of autonomy and empowerment nurses felt in their work.^16^

#### Quality

We identified 1 theme, independent practice expectation, from a single study within the nurse autonomy domain for health care quality (Table 11).^67^ The study focused on experiences of early career nurses, defined as within the first 12 months on the job. Early career nurses described feeling pressure to provide care independently because of limited organizational supports and resources, and self-imposed expectations for professional practice.^67^ The subtheme, seeking assistance, focused on the reticence of nurses to seek and accept help to complete nursing tasks.^67^ The study found that this reticence contributed to delayed patient care among this cohort of early career nurses.^67^

Table 11 Themes of Nursing Autonomy and Quality

Theme | Definition | Exemplar Quotes
Independent Practice Expectation ^67^ | Defined as the provision of care and completion of nursing tasks without peer or supervisor support/assistance because of a self-imposed belief or context-imposed need.; [underlined: Subtheme]; Seeking assistance: Defined as nursing staff actions and behaviors around decision to request help from colleagues and to accept the requested/offered help to complete nursing tasks. | Negative quote: “The newly graduated nurses believed that they were supposed to know how to solve problems and identify appropriate nurse intervention by themselves.”^67^; Negative quote: “Despite being promised mentoring and individual training and introduction to the unit, the newly graduated nurses sometimes experienced that their colleagues were unable to provide support, even if they plucked up the courage to ask for their help.”^67^

#### Safety

We identified 3 themes from 2 studies within the nurse autonomy domain for health care safety (Table 12). The first theme, frontline accountability, was noted in 1 study; this study had significant methodological limitations (see Supplementary Materials). Frontline accountability referred to nursing staff feeling responsible for patient safety, but without the autonomy to impact safety issues.^70^

Another study informed the remaining themes. This study was of sound methodological quality but had limited representation from the care settings sampled (see Supplementary Materials). The theme, advocacy, focused on nurses’ willingness and confidence to communicate assertively to protect the patient.^66^ Nurses described feeling empowered to question, challenge, and oppose care decisions that they deemed unsafe for patients under their care.^66^ The final theme, age and experience, highlighted the impact of lived experience wisdom on nurse autonomy. Nurses described feeling empowered because of their years of practice as a nurse but also due to having a level of wisdom and self-assurance that comes with age; this enabled them to engage in assertive interprofessional communication to ensure patient safety.^66^

Table 12 Themes of Nursing Autonomy and Safety

Theme | Definition | Exemplar Quotes
Frontline Accountability ^70^ | Defined as the responsibility for, or ownership of, safety processes and outcomes held by staff involved in direct patient care whether imposed by the organization or assumed by the individual. | Negative quote: “This can lead to reinforcing professional silos, leaving frontline nurses holding the proverbial ‘patient safety baby’ with minimal autonomy to influence safe practice.”^70^
Advocacy ^66^ | Defined as the willingness to take action and engage in assertive communication behaviors to protect the patient. | Positive quote: “They described the importance of being confident; not following orders when they believed something was not right; […] and taking a firm stance, confidently speaking up and saying ‘no’ when it was unsafe to proceed.”^66^
Age and Experience ^66^ | Defined as the perceived influence a person’s age and professional experience have on their communication behaviors in the workplace. | Positive quote: “When you’re older, you’re more inclined to say, ‘Look. I’m just not budging on this.’ […] If I had been younger or less experienced, I would have done what I was instructed to do, and that wouldn’t have been a good outcome for the patient I don’t believe.”^66^

### Staffing Adequacy

Staffing adequacy encompassed staffing mix, patient-to-nurse ratio, patient assignment or patient acuity, and perceived competency of nursing team. We found that nurses perceive staffing adequacy in their work environment as both positively and negatively impacting health care quality and safety. Nurses’ qualitative views and patterned responses related to the following themes: patient-to-nurse ratios, time constraints, nurse experience, and provision of direct nursing care.

#### Quality

We identified 4 themes within the staffing adequacy domain for quality across 6 studies (Table 13).^67,69,72–74^ The first theme, patient-to-nurse ratios, directly impacts both health care quality and nursing working conditions, including nurse intentions and interactions concerning patient care.^67,69,72,73^ Patient acuity,^67,74^ staffing shortages,^67,73^ and staffing mix^72^ also influence patient-to-nurse ratios. The second theme revealed that time constraints, along with resulting work burden and task overload, are influenced by staffing shortages, and further limit nurses’ time with patients, impacting the quality of patient care.^67,69,72,74^ This is a particularly salient issue with less experienced nurses,^67^ who have challenges balancing work environment demands. Furthermore, time constraints prompt nurses to predominantly focus on patient physical needs, limiting nurses’ interpersonal patient engagement.^67,69^ The third theme, nurse experience, interacts with staffing adequacy, impacting nurses’ emotional well-being. In particular, newly graduated nurses experienced difficulty coping with the emotional pressure from limited time not allowing for high quality patient engagement.^67^ The fourth theme, the provision of direct nursing care is impacted by staffing, limiting interpersonal aspects of direct nursing care, leading to superficial care and prioritizing immediate or physical patient needs.^67,69^ The imbalance between staffing levels and patients’ needs impacts a nurses’ perceived ability and time to provide care,^72^ leading to missed patient information^67^ or unprofessional patient care.^65^

Table 13 Themes of Staffing Adequacy and Quality

Theme | Definition | Exemplar Quotes
Patient-to-Nurse Ratio ^67^ ^,^ ^69^ ^,^ ^72–74^ | Defined as the number of patients versus nurses staffed, including type of patient (ie, acuity, census) and type of staff (ie, staffing mix, overtime) which impacts health care quality. | Positive quote: “Staff recruitment and adequate ward facilities appeared to be critical factors for improving nurses’ work and providing effective and quality care.”^73^; Negative quote: “Staff shortages in combination with a complex patient case mix often hindered nurses from providing the care needed by patients, according to interviewees.”^74^
Provision of Direct Nursing Care ^65^ ^,^ ^67^ ^,^ ^69^ ^,^ ^72^ | Defined as both urgent/non-urgent and clinical/interpersonal aspect of direct nursing care, which are directly influenced by staffing levels and impact health care quality. | Negative quote: “Discrepancies between the number of patients, staff levels and newly graduated nurses’ ideals in relation to patient care routinely deprived the newly graduated nurses of the opportunity to be present and compassionate. These discrepancies reduced the time to deliver direct care, meaning important information about patients’ conditions was missed.”^67^
Time Constraints ^67^ ^,^ ^69^ ^,^ ^72^ ^,^ ^74^ | Defined as the perceived excessive number of nursing tasks and limited time available due to staffing, leading to both time and work constraints, which impact health care quality. | Negative quote: “Too many tasks resulted in direct care where newly graduated nurses predominantly focused on the patients’ physical needs despite recognizing that this compromised the delivery of psychosocial and relational care and subsequently patients’ well-being.”^67^
Nurse Experience ^67^ | Defined as the level of nurse experience (ie, new graduate, nurse mentor), which interacts with staffing levels to impact health care quality. | Positive quote: “I don’t think I have any problems communicating with patients…but there’s just no time for it.”^67^; Negative quote: ““The newly graduated nurse was not capable of coping with the emotional pressure that arose from a sense of not being there for all the patients she had been allocated.”^67^

#### Safety

We identified 4 themes within the staffing adequacy domain for safety across 5 studies (Table 14).^63,64,66,68,70^ The first theme, patient-to-nurse ratios, which includes staffing mix, impacts patient safety^64^ through various means. Adequate staffing ensures patient safety through improved working conditions and the management of nurse workload burden.^63,64,68^ High census numbers and overcrowding also compromises patient safety^63^ and, when encountered, unsafe workloads should be escalated.^70^ Even with technically sufficient staffing, nurses work overtime in order to cover shifts, impacting patient-to-nurse ratios with overworked and burned-out staff.^64^ Time constraints, the second theme, are influenced by staffing, in that sufficient time would provide for safer patient care^63,64^ and improve nurses’ working conditions.^68^ Time constraints also result from an overload of competing tasks, leading to safety concerns.^64^ The third theme, nurses’ experience, interacts with staffing levels to impact safety. Competent, responsible, and experienced staff improve working conditions^68^ and mentorship of beginning nurses supports patient safety.^63^ Experience helps nurses identify gaps in care, building nurses’ awareness, foresight, and intuition, and supporting nurses’ anticipation and management of potential patient issues.^66^ The fourth theme, the provision of direct nursing care, is impacted by staffing adequacy, in that prioritizing direct nursing care can be challenging when there is excessive workload and insufficient time.^64^ This can, in turn, also potentially impact critical patient surveillance^66^ and safety reporting.^64^

Table 14 Themes of Staffing Adequacy and Safety

Theme | Definition | Exemplar Quotes
Patient-to-Nurse Ratio ^63^ ^,^ ^64^ ^,^ ^68^ ^,^ ^70^ | The number of patients versus nurses staffed, including type of patient (ie, acuity, census) and type of staff (ie, staffing mix, overtime) which impacts safety. | Positive quote: “If we had more triage nurses, it would definitely help to manage the workload better and ensure we can provide safe patient care.”^63^; Negative quote: “Sufficient TN must be deployed at the work site to ensure safety. They further stressed the need for more TNs to relieve the burden on existing TNs.”^63^
Provision of Direct Nursing Care ^64^ ^,^ ^66^ | Both urgent/non-urgent and clinical/interpersonal aspect of direct nursing care, which are directly influenced by staffing levels and impact safety. | Positive quote: “Surveillance was described by participants as a complex process with many components: a systematic, comprehensive, head-to-toe and ‘hands on’ approach to patient assessment; nursing vigilance; looking at and observing the whole patient; checking; and making sure.”^66^; Negative quote: “Always, there is always pressure, if not the doctors, the relatives…the workload…it is a lot. If you want to do things right, it is a lot.”^64^
Time Constraints ^63^ ^,^ ^64^ ^,^ ^68^ | The perceived excessive number of nursing tasks and limited time available due to staffing, leading to both time and work constraints, which impact safety. | Positive quote: “They also want more time for triage to identify emergencies and therefore provide better quality and safe care for the patient in the triage area.”^63^; Negative quote: “Yes, it’s very very tough sometimes, very very tough, because, you know, so many patients and we don’t have time and we just run around and doing things and…So it’s easy to miss something.”^64^
Nurse Experience ^63^ ^,^ ^66^ ^,^ ^68^ | The level of nurse experience (ie, new graduate, nurse mentor), which interacts with staffing levels to impact safety. | Positive quote: “There is a greater sense of safety for the TN during the triage process if an older and experienced TN is present to advise, assist and support the TN in learning new TNs. Therefore, they stress that beginners in triage should have a supportive mentor by their side.”^63^

Abbreviations. TN=triage nurse.

### Clarity of Roles and Goals

Clarity of roles and goals was defined as the extent to which nurses knew what to expect during their shifts and how clearly these rules and policies about roles were communicated to others in the organization. This domain included clarity of roles and goals among those in the nursing profession and those interacting with nurses, such as other health care staff and administrators.

#### Quality

We identified 3 themes within the clarity of roles and goals domain for quality across 2 studies (Table 15).^67,73^ The first theme centered on the nursing role of direct patient care.^67^ This theme was based on 1 study focused on the experiences of registered nurses in the first 12 months on the job. New nurses prioritized direct patient contact as a way to build a trusting relationship with their patients. Even if tasks could be delegated, or other staff offered to assist in patient care tasks, new nurses still prioritized direct patient care. New nurses felt that continuity of care, operationalized as 1 person (eg, the RN) doing the direct patient care tasks, was key to developing a trusting relationship with patients. The next theme, job description clarity, also was only present in 1 study and focused on the role of clear task delineation in the provision of quality care.^73^ Nurses perceived that miscommunications with other non-nursing staff and a lack of clarity in job descriptions led to negative impacts on health care quality. The last theme was the multidimensional scope of nursing and was present in 1 study.^73^ Nurses reported that they had a clear role in delivering quality care driven by job descriptions, protocols, and quality improvement processes. This theme included a subtheme of personal responsibility for patients under their care. Feeling personally accountable for patient care was viewed as a consistent thread across all dimensions of nursing and a key ingredient in the provision of high-quality nursing care. Yet, nurses felt that not everyone outside of the nursing profession understood their role in delivering quality care.

Table 15 Themes of Clarity of Roles and Goals and Quality

Theme | Definition | Exemplar Quotes
Direct Patient Contact ^67^ | The provision of direct patient care by nurses on perceived health care quality. | Negative quote: “I find it difficult to delegate those little things you can do for the patient during the day and where you make contact and establish a relationship. I think patients are most comfortable with the fact that it is the same person that comes and does it all.”^67^
Job Description Clarity ^73^ | The role of clear task delineation in provision of quality care. | Negative quote: “Miscommunication with other professionals,…and unclear job description…these have a negative impact on care.”^73^
Multidimensional Scope of Nursing ^73^ | The multifaceted domains of nursing that impact the delivery of quality health care.; [underlined: Subtheme]: Personal responsibility | Positive quote: “We need to realize what our job is about. It is a matter of character…unfortunately not everyone can understand what our job involves and how we can do things in the right way…that we should work according to protocols, to have audits, to be responsible for the care provided to the patients and for the work doing in the clinic. It is important each of us realize that our practice, reflects to patient condition, to patients’ life, to care provided.”^73^

#### Safety

We identified 2 themes within the clarity of roles and goals domain for patient safety across 3 studies (Table 16).^63,68,70^ The first theme focused on the role of personal responsibility expressed as a duty to foster, and accountability for, patient safety and was derived from 2 studies.^63,70^ Nurses felt a clear responsibility to deliver safe patient care as a matter of their role on the health care team.^70^ As nurses, they view patient safety as a part of the mission of their profession.^63^ The last theme was only present in 1 study and focused on the use of information in patient safety.^68^ The effective use of information by nurses was viewed as essential to ensuring patient safety. Nurses expressed that better information flow, feedback opportunities, and improvement planning were needed to optimize use of information for nursing care.

Table 16 Themes of Clarity of Roles and Goals and Safety

Theme | Definition | Exemplar Quotes
Personal Responsibility ^63^ ^,^ ^70^ | The role of nursing as a duty to, and accountability for, patient safety. | Positive quote: “The RNs spoke of their own accountability and responsibility for patient safety as an individual role unique to nursing. This was attached to integrity of nursing practice.”^70^
Use of Information ^68^ | Role of the use of information by nurses on patient safety. | Positive quote: “A better flow of information and opportunity for feedback; improvement of surgical planning.”^68^

### Recognition

We defined recognition as the respect and rewards nurses receive for their effort and contributions in the workplace. We found that nurses find patient recognition to be an indicator of health care quality and colleague recognition to be a positive influence on health care quality. Nurses’ qualitative views and patterned responses related to the following themes: feedback from patients and acknowledgment from colleagues.

#### Quality

We identified 2 themes, both positive in valence, within the recognition domain for quality across 1 study (Table 17).^73^ The first theme, feedback from patients, indicates the role of patient feedback as an indicator of the quality of nursing care.^73^ The second theme, acknowledgment from colleagues, is a factor influencing the quality of the care provided by nurses.^73^ Recognition nurses receive from both patients and colleagues contributes to the provision of quality care and enhanced nurse job satisfaction.

Table 17 Themes of Recognition and Quality

Theme | Definition | Exemplar Quotes
Feedback from Patients | Role of expressions of patient gratitude as an indicator of the quality of the care provided by nurses. | Positive quote: “To communicate with the patient and have recognition for my work, to get a thank you at the end of the day…this is quality at work.”^73^
Acknowledgment from Colleagues | Role of acknowledgments from colleagues as a factor influencing the quality of the care provided by nurses. | Positive quote: “recognition of their work from…other professionals, and cooperation with colleagues during work shifts, impact positively on the provision of optimal nursing care and enhanced nurses’ job satisfaction.”^73^

#### Safety

None of the studies prioritized for analysis reported themes related to recognition and perceptions of safety.

### Physical Comfort

We defined physical comfort as the availability and adequacy of equipment, materials, technological tools, supplies, and other non-human resources in the nurse work environment.

#### Quality

We identified 2 themes within the physical comfort domain for quality across 2 studies (Table 18).^69,72^The first theme, environment noise level, is a factor influencing both the quality of care provided by nurses, along with influencing patient well-being.^69^ For example, the emergency department was considered as having higher levels of environmental noise. While some practical nursing tasks could still be completed at this level of noise, other nursing tasks, such as communication with patients and others, were negatively impacted by the noise levels in the environment.^69^ Further, these noise levels were also attributed to increasing patient agitation, which also negatively influences nurses’ physical comfort. The second theme, environment resources, was also a key factor influencing the quality of nursing care: deficits in supplies impacted care quality.^72^

Table 18 Themes of Physical Comfort and Quality

Theme | Definition | Exemplar Quotes
Environment Noise Level | Role of noise levels as a factor influencing both the quality of care provided by nurses, along with patient well-being. | Positive quote: “If you’re doing a blood pressure it doesn’t matter if someone’s screaming in the hallway.”^69^; Negative quote: “But if you’re asking about their childhood trauma…you’d rather be in a quieter room or somewhere that feels more private.”^69^
Environment Resources | Role of environment resources available as a factor influencing the quality of care provided by nurses. | Negative quote: “Nurses were stressed that they could not do their jobs well, or in a timely fashion, due to time constraints or lack of supplies.”^72^

#### Safety

We identified 3 themes within the physical comfort domain for safety across 3 studies (Table 19).^63,64,70^The first theme, environment attributes, indicates the role that attributes such as perceived physical safety, layout, and available equipment play in influencing safe nursing care.^63,70^ Environment interruptions, such as incoming calls interrupting the nursing work process, is a second theme perceived to influence safe nursing care.^63^ Conversely, staff-specific physical spaces, the third theme, suggests that a separate physical space for staff to take breaks may work to positively influence safe nursing care.^64^

Table 19 Themes of Physical Comfort and Safety

Theme | Definition | Exemplar Quotes
Environment Attributes | The role of physical safety, layout, and available equipment in the nursing environment as factors influencing safe nursing care. | Positive quote: “The physical environment and equipment were often highlighted in the workplace as patient safety factors in the triage process. For safe triage, a sufficient room size with wide doors is essential, which is comfortable for the patient and the TN, equipped with a bed with safety bed rails. They emphasize that the devices must be adequate, functional, calibrated, reliable and regularly inspected.”^63^; Negative quote: “For a number of participants, being under siege occurred in their physical working space, such as their ward. In these groups, they spoke of protection to enable them to do what they needed to do. Their concerns about physical safety are connected with their working environment and patient cohort.”^70^
Environment Interruptions | The role of interruptions in the nursing environment as a factor influencing safe nursing care. | Negative quote: “We are also distracted by telephones, which constantly interrupt the work process.”^63^
Staff-Specific Physical Spaces | The role of separate physical spaces for staff to take breaks as a factor influencing safe nursing care. | Positive quote: “In the unit there are lot of pressure. The nurses have a staff room for breaks, so the pressure does not put at risk the patient.”^64^

Abbreviations. TN=triage nurse.

### Flexible Scheduling

None of the studies prioritized for analysis reported themes related to flexible scheduling and perceptions of quality or safety.

### Organizational Culture

Organizational culture was defined as the social conditions, social norms, informal rules, and formal policies of the organization that influenced the nurse work environment.

#### Quality

We identified 3 themes within the organizational culture domain for health care quality across 2 studies (Table 20). Both studies recognized the first theme, influence of workplace culture on the nurse, and by extension the impact on the quality of care.^67,74^ Nurses regarded the influence of culture as “facilitating or hindering the achievement of good care.”^74^ Early career nurses expressed difficulty staying present with patients when providing care in units with contentious cultures.^67^ The second theme, practice gap, focused on deviations from care standards and professional ideals that occur as a result of the unit culture. This theme was identified in 1 study where early career nurses found themselves adapting to a culture of delayed care.^67^ The third theme, workplace over patient, was highlighted in the same study.^67^ Early career nurses described a culture of prioritizing the organization over acute patient needs; this manifested as attending to standard procedures, rounding routines, and policy with greater urgency than patient care needs.^67^

Table 20 Themes of Organizational Culture and Quality

Theme | Definition | Exemplar Quotes
Influence of Workplace Culture on the Nurse ^67^ ^,^ ^74^ | Defined as how organizational culture of unit shapes nurse attitudes, behaviors, practice patterns, and subsequent interactions with staff and patients. | Neutral quote: “Nurses referred to administrative and social rules that shaped their work environment. In each ward, there were written and unwritten social rules that imposed a time schedule and organizational rules regarding care planning.”^74^
Practice Gap ^67^ | Defined as the influence of unit organizational culture on nurse behaviors that result in deviations from care standards and/or professional ideals. | Negative quote: “Although it [the prescription] says that the medicine should be administered at 12 o’clock. If it is not vital, I can allow myself, like the others, to postpone it [medication administration] and sometimes I do. But I am also afraid that if I choose to compromise my ideals, what will happen in 5 years? The culture tries to dominate my ideals.”^67^
Workplace Over Patient ^67^ | Defined as decision-making, and subsequent behaviors from those decisions, that prioritizes or is heavily influenced by the wants/needs of the workplace (eg, self, other personnel, procedures, practices) over/more so than patient care needs. | Negative quote: “I know it’s poor care, but if I don’t do rounds now, it will have major consequences for me later where I must do the documentation.”^67^

#### Safety

We identified 5 themes within the organizational culture domain for health care safety across 2 studies (Table 21). The first theme in this domain centered on nurse perceptions of the organizational response to error and was noted in both studies.^64,70^ In 1 study, nurses perceived the organizational response to error as punitive and expressed aversion to reporting errors as a result.^64^ The second study presented the organizational response to error as a driver for learning and reflection in efforts to improve patient safety.^70^

The remaining themes were identified in the second study,^70^ which was found to have significant methodological limitations (see Supplementary Materials). The second theme, trust and support, defined a culture where nurses can express concerns and feel heard when they do so.^70^ The third theme, frontline accountability, focused on the how the responsibilities to ensure patient safety are often transferred to the patient-facing staff as opposed to being a part of a broader organizational accountability.^70^ The fourth theme, shared language, referred to the concept that patient safety-focused language between nursing staff and the organization influenced the workplace culture around safety.^70^ This shared aspect of the organizational culture was demonstrated via known terminology used in the workplace (eg, safety “audits, guidelines, best practices”).^70^ Education and training, the final theme, highlighted the utility of education on safety practices to promote patient safety.^70^

Table 21 Themes of Organizational Culture and Safety

Theme | Definition | Exemplar Quotes
Organizational Response to Error ^64^ ^,^ ^70^ | Defined as experiences and perceptions of organizational actions, or the lack thereof, in response to workplace errors (eg, adverse events). | Negative quote: “For example, they give a warning to the nurse if she makes a mistake. And she has to participate in training. If something happens in the unit, they have to speak about it to avoid it happening again.”^64^
Trust and Support | Defined as the felt sense and experience of being listened to when expressing needs and concerns regarding patient care. | Positive quote: “Staff are connected both with a request for organizational support and trust for work activities that are significant to them.”^70^
Frontline Accountability ^70^ | Defined as the responsibility for, or ownership of, safety processes and outcomes held by staff involved in direct patient care whether imposed by the organization or assumed by the individual. | Negative quote: “The accountability for this is often transferred to individuals or specific clinician roles.”^70^
Shared Language ^70^ | Defined as the common communication system (eg, vocabulary, topics) between individual staff and the organization that indicates mission and/or priority alignment. | Positive quote: “Their language consisted of audits, guidelines, best practices, training, patient journeys, and reducing staff errors […], the nurses’ discourse reflected the embedded language within the whole organization.”^70^
Education and Training ^70^ | Defined as the availability of, participation in, or desire for knowledge and skill acquisition necessary for job performance. | Neutral quote: “Education can be seen as the catch-all solution for patient safety.”^70^

### Professional Development Opportunities

We defined professional development opportunities as nurse descriptions of educational or experiential opportunities to support personal growth and professional goals.

#### Quality

We identified 1 theme and 2 subthemes related to nursing perceptions of the impact of professional development opportunities on health care quality. Education and training was defined as the availability of, participation in, and desire for knowledge and skill acquisition necessary for job performance, and it can be further understood through the subthemes of inadequate education and training and experiential learning (Table 22). The 3 studies that considered this workplace factor recognized education and training as impactful to the quality of nursing practice.^63,69,73^ The subthemes emerged from 1 of the studies. They presented as nursing staff recognizing their limitations when working with specific populations, such as individuals with mental health diagnoses, as a result of inadequate education and training (subtheme): “I don’t even know if there are any resources to be honest. I think it’s just deal with it as best as you can.”^69^ Additionally, knowledge and skill acquisition through informal observation of colleagues and trial and error in individual nursing practice (subtheme: experiential learning) served as sources of education and training.^69^

#### Safety

We identified the theme of education and training and the subtheme of inadequate education and training, related to nursing perceptions of the impact of professional development opportunities on health care safety. Similar to the impact on health care quality, professional development opportunities in the form of education and training were viewed as essential to ensuring health care safety.^63,70^ The subtheme of inadequate education and training emerged from 1 of 2 studies that explored nursing perceptions related to professional development opportunities and health care safety (Table 22).

Table 22 Themes of Professional Development and Quality and Safety

Theme | Definition | Exemplar Quotes
Education and Training | The availability of, participation in, or desire for knowledge and skill acquisition necessary for job performance.; [underlined: Subthemes]; Inadequate education and training: The absence of adequate education and training necessary for confidence in job performance and professional development.; Experiential learning: Knowledge or skill acquisition through the experience of observing colleagues or through trial and error in professional practice whether done formally or informally. | Negative quote: “The staff needs to be trained to be able to cope with critical situation to have the knowledge and the skill. This would help to deliver better quality of care.”^73^; Negative quote: “Triage training gave them the basics of what triage should look like but not enough knowledge to triage confidently and safely by themself.”^63^; Neutral quote: “I was never taught how to actually ask the questions or what questions to ask…it’s more just the experience of listening and knowing…what I’ve asked before and the answers that I’d gotten in the past with what’s worked.”^69^

### Salary

We defined salary as the monetary compensation that nurses received for their work, inclusive of benefits and wages.

#### Quality

We did not identify any studies that assessed nurses’ perceptions of salary on health care quality.

#### Safety

We identified 1 theme, payment-workload tension, from a single study within the salary domain for health care safety (Table 23).^64^ The theme highlighted the tension between completing clinical duties and extra duties related to safety procedures, during compensated time.^64^ The study presented nursing staff perceptions from a variety of inpatient and outpatient settings in 4 European Union countries.^64^

Table 23 Themes of Salary and Safety

Theme | Definition | Exemplar Quotes
Payment and Workload Tension ^64^ | Defined as the association between payment structure (eg, payment for specific tasks or not) and workload that influences the ability of nurses to complete tasks required to deliver safe care. | “Although Spanish nurses are paid for their time, they were not always able to make the time to review clinical records due to the increased workload compared to Sweden.”^64^

### Participation in Decision-Making

None of the studies prioritized for analysis reported themes related to participation in decision-making as a workplace factor and perceptions of quality or safety.

### Innovation

None of the studies prioritized for analysis reported innovation as a workplace factor and perceptions of quality or patient safety.

### Workplace Safety and Violence

Workplace safety and violence was defined as “the absence of prevention of violence in the work environment of nurses.”^16^

#### Quality

None of the studies prioritized for analysis reported themes related to workplace safety and quality.

#### Safety

We identified 1 theme from a single study within the workplace safety and violence domain for patient safety (Table 24).^70^ The theme, individual and collective safety, centered the need for safe environments for all parties involved in care—patients, family, and staff. The study focused on clinical nurse perceptions from a variety of hospital settings.^70^

Table 24 Themes of Workplace Safety and Safety

Theme | Definition | Exemplar Quotes
Individual and Collective Safety ^70^ | Defined as the identified need for all key partners to feel safe in the working environment to ensure safe care. | “This point is highlighted by their addition of ‘staff too’ to the comment ‘ensuring patient and family are safe and supported.’”^70^

### Emerging Nurse Definitions of Quality and Safety

We also explored how nurses are conceptualizing health care quality and patient safety.

#### Quality

We identified 1 theme from the 2 studies exploring nurse-defined quality of care (Table 25).^72,73^ The theme, quality defined by relationship, focused on the nursing staff’s desire to provide compassionate and respectful care to meet the holistic needs of patients through nursing interactions with patients, colleagues, workplace culture, and organizational policies, practices, and resources.^72,73^ Both studies included a mix of inpatient and outpatient nursing staff.

Table 25 Themes of Nurse Definitions of Quality

Theme | Definition | Exemplar Quotes
Quality Defined by Relationship ^72^ ^,^ ^73^ | Defined as holistic patient care involving empathy, respect, and compassion that leads to positive patient outcomes as a result of nurse relationships with individuals, workplace culture, and organizational structures and resources. | “They defined quality as a holistic approach to patient care, involving issues of communication, best patient outcome, competency, knowledge, satisfaction, and meeting the patient’s needs.”^73^

#### Safety

##### Definitions of Safety

One study described definitions of patient safety and focused on the importance of safety culture on patient safety practices (Table 26). The study cited both World Health Organization (WHO) and Australian Commission on Safety and Quality in Health Care definitions and described safety as the framework of organizational policies and structures that co-occur with patient safety culture to reduce the likelihood of unsafe events.^70^ The study focused on nursing staff perceptions from a variety of inpatient settings.

Table 26 Themes of Nurse Definitions of Safety

Theme | Definition | Exemplar Quotes
Safety Culture Defines Patient Safety ^70^ | The organizational policies and structures to reduce overall harm, error, and risk in patient care that co-occur with individual and group behaviors associated with patient safety culture. | “The relationship between safety culture and patient safety is complex; however, a positive culture is associated with improved patient outcomes by limiting unsafe practices.”^70^

### Other Workplace Domains

The other domain is defined as the factors, which are emerging or new from the a priori 14-factor workplace typology used to categorize all other data.

#### Quality

The confluence of multiple workplace factors on health care quality is an emerging theme that can be found in 3 studies (Table 27).^65,73,74^ The first study discussed an element of time pressure, which was influenced by multiple organizational factors such as culture, leadership, and staffing.^74^ Time pressure generated a sense of constantly being behind and having to focus on the physical needs of patients rather than the holistic care that the nursing staff desired to provide.^74^ The second example was described by the nurses broadly as nursing “working condition” but did not offer any other clarification.^65,73^

Table 27 Themes of Other Workplace Domains and Quality

Theme | Definition | Exemplar Quotes
Confluence of Multiple Workplace Factors ^65^ ^,^ ^73^ ^,^ ^74^ | Defined as interaction and impact of more than 1 workplace factor on quality. | No primary quote.

#### Safety

The confluence of multiple workplace factors on patient safety is an emerging theme that can be found in 3 studies (Table 28).^63,68,70^ There was an element of time pressure’s impact on safety due to nurse “working conditions”, which were not further delineated.^68^ Additionally, there was a thread related to processes used by the nurses to maintain safety.^63^ Examples of these safety practices included checking identification and providing ongoing monitoring, but the drivers of these processes were not identified.^63^ Both of these examples point to the possibility that multiple workplace factors (eg, professional development or organization policies) may be involved and act synergistically to positively or negatively impact patient safety.

Table 28 Themes of Other Workplace Domains and Safety

Theme | Definition | Exemplar Quotes
Confluence of Multiple Workplace Factors ^63^ ^,^ ^68^ ^,^ ^70^ | Defined as interaction and impact of more than workplace factor on patient safety. | No primary quote.

### CERQual

We conducted CERQual ratings for the findings aligned with stakeholder-prioritized workplace factors identified across the KQ1b studies with adequate richness (Tables 29A and 29B). Overall, our COE ranged from high confidence to very low certainty, downgraded for methodological limitations, adequacy, and relevance. Five studies with quality outcomes reporting the teamwork skills theme and the 5 quality studies reporting the team relationships theme were rated as high confidence for no/very minor concerns across coherence, adequacy, limitations, and relevance categories. However, 5 studies reporting nurse-to-patient ratios and quality of care were evaluated as moderate confidence because of serious concerns regarding relevance, as 4 of the studies analyzed data from countries where nursing scope of practice may differ from the US. One study reporting data that fit into the nurse experience theme was evaluated low confidence given moderate concerns regarding adequacy of data and serious concerns regarding relevance for non-US based data as well. The 3 studies describing leadership support had some moderate concerns around adequacy and minor concerns regarding relevance, as none of the studies were US-based, and were evaluated with moderate confidence.

Across the studies reporting health care safety, 4 studies reporting data in the teamwork skills and the team relationships themes were evaluated with moderate confidence, given methodological concerns and concerns of data adequacy. The 5 safety studies reporting nurse-to-patient ratios faced minor concerns regarding methodological limitations and minor concerns of relevance, and were thus rated as moderate confidence. Three studies in the nurse experience theme and reporting safety were downgraded for minor concerns regarding adequacy, methodological limitations, and relevance. We had low confidence in the 2 studies reporting the finding of leadership support, given moderate concerns regarding adequacy, methodological limitations, and relevance. For the finding of age and experience, only 1 non-US-based study reported health care safety, and this study was evaluated as low confidence given serious concerns regarding adequacy and relevance.

Table 29A CERQual Summary of Available Evidence for KQ1b: How Do Nurses Perceive That Their Work Environment Impacts Health Care Quality?

Workplace Factor; Studies (Participants) | Definition of Theme | Coherence | Adequacy | Limitations | Relevance | Confidence of Evidence
Teamwork; 5 studies (191) | Teamwork skills; Defined as the techniques required by nurses to successfully practice with a health care team to deliver safe and effective care. | No/Very minor concerns regarding coherence | No/Very minor concerns regarding adequacy | No/Very minor concerns regarding methodological limitations | No/Very minor concerns regarding relevance | High confidence
Teamwork; 5 studies (61) | Team relationships; Defined as the ways in which team members interact with one another and their influence on patient safety and quality. | No/Very minor concerns regarding coherence | No/Very minor concerns regarding adequacy | No/Very minor concerns regarding methodological limitations | No/Very minor concerns regarding relevance | High confidence
Staffing Adequacy; 5 studies (61) | Nurse-to-patient ratios; Defined as the number of patients versus nurses staffed, including type of patient (ie, acuity, census) and type of staff (ie, staffing mix, overtime) which impacts health care quality. | No/Very minor concerns regarding coherence | No/Very minor concerns regarding adequacy | No/Very minor concerns regarding methodological limitations | Serious concerns regarding relevance | Moderate confidence
Staffing Adequacy; 1 study (10) | Nurse experience; Defined as the level of nurse experience (ie, new graduate, nurse mentor), which interact with staffing levels to impact health care quality. | No/Very minor concerns regarding coherence | Moderate concerns regarding adequacy | No/Very minor concerns regarding methodological limitations | Serious concerns regarding relevance | Low confidence
Leadership; 3 studies (48) | Leadership support; The impacts that leadership support has on procurement of resources (eg, staff) and setting a tone/culture for health care quality. | No/Very minor concerns regarding coherence | Moderate concerns regarding adequacy | No/Very minor concerns regarding methodological limitations | Minor concerns regarding relevance | Moderate confidence
Nursing Autonomy; 1 study (10) | Independent practice expectation; Defined as the provision of care and completion of nursing tasks without peer or supervisor support/assistance as a result of a self-imposed belief or context-imposed need. | No/Very minor concerns regarding coherence | Serious concerns regarding adequacy | No/Very minor concerns regarding methodological limitations | Serious concerns regarding relevance | Very low confidence

Table 29B CERQual Summary of Available Evidence for KQ1b: How Do Nurses Perceive That Their Work Environment Impacts Health Care Safety?

Workplace Factor; Studies (Participants) | Definition of Theme | Coherence | Adequacy | Limitations | Relevance | Confidence of Evidence
Teamwork; 4 studies (549) | Teamwork skills; Defined as the techniques required by nurses to successfully practice with a health care team to deliver safe and effective care. | No/Very minor concerns regarding coherence | Moderate concerns regarding adequacy | Moderate concerns regarding methodological limitations | No/Very minor concerns regarding relevance | Moderate confidence
Teamwork; 4 studies (549) | Team relationships; Defined as the ways in which team members interact with one another and their influence on patient safety and quality. | No/Very minor concerns regarding coherence | Moderate concerns regarding adequacy | Moderate concerns regarding methodological limitations | No/Very minor concerns regarding relevance | Moderate confidence
Staffing Adequacy; 5 studies (569) | Nurse-to-patient ratios; Defined as the number of patients versus nurses staffed, including type of patient (ie, acuity, census) and type of staff (ie, staffing mix, overtime), which impacts health care quality. | No/Very minor concerns regarding coherence | No/Very minor concerns regarding adequacy | Minor concerns regarding methodological limitations | Minor concerns regarding relevance | Moderate confidence
Staffing Adequacy; 3 studies (448) | Nurse experience; Defined as the level of nurse experience (ie, new graduate, nurse mentor), which interacts with staffing levels to impact health care quality. | No/Very minor concerns regarding coherence | Minor concerns regarding adequacy | Minor concerns regarding methodological limitations | Minor concerns regarding relevance | Moderate confidence
Leadership; 2 studies (382) | Leadership support; The impacts that leadership support has on procurement of resources (eg, staff) and setting a tone/culture for health care quality. | No/Very minor concerns regarding coherence | Moderate concerns regarding adequacy | Moderate concerns regarding methodological limitations | Moderate concerns regarding relevance | Low confidence
Nursing Autonomy; 1 study (71) | Age and experience; Defined as the perceived influence a person’s age and professional experience have on their communication behaviors in the workplace. | No/Very minor concerns regarding coherence | Serious concerns regarding adequacy | No/Very minor concerns regarding methodological limitations | Serious concerns regarding | Low confidence

## KEY QUESTION 2 WHAT NURSE WORK ENVIRONMENT INTERVENTIONS OR STRATEGIES ARE AVAILABLE TO IMPROVE NURSE-RATED HEALTH CARE QUALITY AND SAFETY?

Nine eligible studies^119,138–145^ reported interventions that addressed at least 1 of the 14 nurse workplace factors (see Supplementary Materials) and evaluated nurse-rated safety or quality. The number of workplace factors impacted by these interventions ranged from 6 to 2 with a median of 3. The most commonly involved workplace factor was teamwork (k = 7),^119,139,140,142–145^ the next most commonly reported factors were leadership (k = 4),^119,139,141,144^ nursing autonomy (k = 4),^119,138,143,144^ and clarity of roles and goals (k = 4).^139–141,143^ Innovation was reported by 3 studies^139,141,142^ and organizational stability or culture (k = 1),^119^ physical comfort (k = 1),^141^ and participation in decision-making (k = 1)^144^ were the least frequently impacted. While all interventions used unique packages of strategies, all used some form of process improvement that engaged the organizations’ leadership and was inclusive of evaluation and feedback (eg, audit and feedback, implementing tool for quality monitoring), training (eg, conducting didactic educational sessions, providing ongoing consultation from expert peer), and communication (eg, improving handover processes between nursing shifts, developing interdisciplinary care rounds) approaches.