# METHODS

## REGISTRATION AND REVIEW

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (CRD420251014455 (https://www.crd.york.ac.uk/PROSPERO/view/CRD420251014455)). A draft version of this report was reviewed by external peer reviewers; their comments and author responses are provided in the Supplementary Materials.

## KEY QUESTIONS AND ELIGIBILITY CRITERIA

The following key questions were the focus of this review:

- Key Question 1a (KQ1): What is the impact of nurse work environment characteristics on nurse-rated health care quality and safety?
- Key Question 1b (KQ1b): How do nurses perceive that their work environment impacts health care quality and safety?
- Key Question 2 (KQ2): What nurse work environment interventions or strategies are available to improve nurse-rated health care quality and safety?

Study eligibility criteria are shown in Table 1.

Table 1 Eligibility Criteria

Domain | Inclusion Criteria | Exclusion Criteria
Population | Nurses (ie, RN) providing care to adults in the inpatient or outpatient health care setting; If study population is comprised of a mix of nursing professionals who meet exclusion and inclusion criteria (eg, advanced practice nurses and RNs; pediatric and adult care nurses), studies will only be included if they 1) have 80% or more of nursing professional who meet eligibility or 2) include a subgroup analysis of nursing professionals who meet inclusion criteria. | Studies focused on these staff:; Advanced practice nurses (eg, NP, Certified Nurse-Midwife, Certified Registered Nurse Anesthetist, Clinical Nurse Specialist); Nursing assistants, LPN, LVN; Nurse managers; Travel nurses; Nursing students
Intervention | KQ1a & b: Nurse work environment factors identified by nurse that may impact nurse-rated health care quality and/or safety.; KQ2: Interventions or strategies deployed at a clinic or higher level and focused on aspects of the nurse work factors and impacts on nurse-rated health care quality and/or safety.; Nurse work environment must encompass one of the following factors^a^:; Teamwork (positive working relationships among nursing team and other personnels, peer cohesion or social support);; Leadership (supervisor or leadership support, communication, or feedback or leadership style);; Nurse autonomy (how autonomous or empowered nurses felt in their work);; Staffing adequacy (staffing mix, patient-to-nurse ratio, patient assignment or patient acuity, competency of nursing team);; Clarity of roles and goals (extent to which employees know what to expect in their daily routine [role clarity] and how explicitly rules and policies are communicated [goal clarity];; Recognition (respect and rewards received for their jobs);; Physical comfort (availability and adequacy of equipment, materials, technological tools, supplies and other non-human resources);; Flexible scheduling;; Organizational culture;; Professional development opportunities (career development/laddering, and education to support personal growth and professional goals);; Salary;; Participation in decision-making (nurse participation in organizational or clinical decision-making);; Innovation (degree of variety or change, and new approaches impacting workplace);; Workplace safety and violence (degree of violence in the workplace or prevention of violence in the workplace) | KQ1 & KQ2:; Focus on personal characteristics of nurses (eg, experience, marital status, race/ethnicity, stress levels, work-life balance, self-image, values); Focus on work environment indicators (eg, job satisfaction, decreased turnover, absenteeism, burnout); Focus on impact of COVID-19 pandemic on health care quality; KQ2:; Deployed at an individual level
Comparator | KQ1: Any or no comparators; KQ2:; Usual care/standard of care, waitlist control, historical controls Other active comparator | KQ2: No comparator
Outcomes | KQ1a & KQ2:; Nurse-rated health care quality; Nurse-rated patient safety; KQ1b: Nursing staff experiences or perceptions of how nurse work environment influences:; Nurse-perceived health care quality; Nurse-perceived patient safety | Any outcomes not listed; Only objective measures of health care quality and/or safety (eg, falls, infection rates, mortality) without any nurse-reported ratings; Occupational safety
Context | KQ1 & KQ2:; Outpatient health care (ie, primary and specialty care; emergency room; home health and home visits); Inpatient health care setting (ie, critical care; acute care, long term care); OECD countries^b^ | Health care provided in these settings:; Carceral institutions; Colleges or universities; Less than 80% OECD countries
Timing | Article published after 2013^c^ | Article published before 2014
Study Design | KQ1a (quantitative studies):; Cross-sectional surveys; Uncontrolled clinical study; Retrospective pre-post study; KQ1b (Qualitative studies):; Qualitative studies (eg, qualitative interviews, focus groups, observations, organizational case studies); Ethnographies; Mixed methods studies that report qualitative findings; KQ2:; Randomized trials; Nonrandomized trials; Controlled before-after studies; Interrupted time-series studies or repeated measures studies that must have more than one measurement before and after intervention implementation; Prospective and observational studies (ie, cohort studies, case control studies); Uncontrolled before and after studies (ie, pre-post study) | KQ1 & KQ2:; Not a clinical study (eg, editorial, non-systematic review, letter to the editor); Systematic reviews; Clinical guidelines; Protocol papers; Measurement or validation studies (eg, scale developments studies)

Notes.

a Workplace factors were informed by the nursing work environment described by Schalk et al 2010.^16^;

b Organisation for Economic Cooperation Development countries = Australia, Austria, Belgium, Canada, Chile, Colombia, Costa Rica, Czech Republic, Denmark, Estonia, Finland, France, Germany, Greece, Hungary, Iceland, Ireland, Israel, Italy, Japan, Korea, Latvia, Lithuania, Luxembourg, Mexico, Netherlands, New Zealand, Norway, Poland, Portugal, Slovak Republic, Slovenia, Spain, Sweden, Switzerland, Turkey, United Kingdom, United States;

c We constrained our search to studies published after January 1, 2014, to align with currents standards in nursing care and nursing workplace environments (eg, Quality and Safety Education for Nurses (QSEN) initiative that integrated quality and safety competencies into nursing education).^23^

## SEARCHING AND SCREENING

To identify articles relevant to the key questions, a research librarian searched MEDLINE (via Ovid), Scopus (Elsevier), and CINAHL Ultimate (EBSCO) to identify manuscripts published between January 1, 2014, to December 16, 2024, using terms for health care quality and patient safety (eg, patient harm, patient quality) as well as nurse work environment (eg, safety climate) (see Appendix for complete search strategies). To ensure completeness, search strategies were developed in consultation with an expert medical librarian and peer reviewed by a second librarian in accordance with Peer Review of Electronic Search Strategies (PRESS) guidance.^24^ Titles, abstracts, and full-text articles were independently reviewed by 2 investigators, and disagreements were resolved by a third reviewer or consensus.

## DATA ABSTRACTION AND RISK OF BIAS ASSESSMENT

Population, workplace factors, outcome measures, and effect information were abstracted from included studies as applicable. Data were abstracted into Covidence by 1 reviewer and over-read by a second reviewer. Disagreements were resolved by consensus or by obtaining a third reviewer’s opinion when consensus could not be reached between the first and second reviewers. The risk of bias (ROB) of the KQ1a studies included for analysis were rated using the National Institutes of Health (NIH) Quality Assessment Tool for Observational Cohort and Cross-Sectional Studies.^25^ The NIH tool includes 14 questions about the population of interest and participation rate, the power or sample size, the timeframe and temporal relationship between exposure and outcome, consistency and reliability of exposure, outcome, and confounder measures, blinded outcome assessment, and loss to follow-up. The NIH tool also includes an overall quality rating of good, fair, or poor. For KQ1b, we used the Critical Appraisal Skills Programme (CASP)^26^ tool for qualitative designs. The CASP tool includes the following questions: (1) Was there a clear statement of the aims of the research? (2) Is the qualitative methodology appropriate? (3) Was the research design appropriate to address the aims of the research? (4) Was the recruitment strategy appropriate to the aims of the research? (5) Was the data collected in a way that addressed the research issue? (6) Has the relationship between researcher and participants been adequately considered? (7) Have ethical issues been taken into consideration? (8) Was the data analysis sufficiently rigorous? (9) Is there a clear statement of findings? (10) How valuable is the research? For KQ1a, ROB ratings were completed by 2 independent reviewers; disagreements were resolved by consensus or discussion with a third reviewer. For KQ1b, ROB ratings were assessed by 1 reviewer and over-read by a second reviewer (see the Supplementary Materials for risk of bias ratings). We did not evaluate the ROB of the studies identified for KQ2 as is the methodological standard of evidence mapping reviews.

## SYNTHESIS

We summarized the primary literature using relevant data abstracted from the eligible studies. We constructed summary tables (KQ1a, KQ1b, KQ2) to describe the key study characteristics of the studies: study design, nurse demographics, and details of the work environment and outcome measures. We determined the feasibility of completing a quantitative synthesis (ie, meta-analysis) to estimate summary effects of studies included for KQ1a. Given the large number of includes identified and the changes in nursing practice in recent years, we prioritized studies for analysis with data collected since 2018 or published after 2017. Regression weights are standardized (SRW) unless otherwise specified.

For KQ1a, we aggregated outcomes when there were at least 3 studies with the same outcome, based on the rationale that 1 or 2 studies do not provide adequate evidence for summary effects. We grouped work-related exposures into conceptually similar workplace factors. The 14 workplace factors were specified a priori and informed by a previous systematic review.^16^ When a study assessed 2 or more nurse workplace factors as a single exposure, we grouped these into a domain called “global” and analyzed these together. A group of investigators (JMG, TD, IS, AMG) with interdisciplinary expertise verified that workplace factors were assigned with internal consistency across the studies analyzed, including common measures used in the field of nursing scholarship. Table 2 shows the categorization schema of the Hospital Survey on Patient Safety Culture (HSOPSC) subscales using the workplace factor categories used in this report.^27^ Table 3 shows subscales of the Practice Environment Scale of the Nursing Work Index (PES-NWI) and the workplace factors.^28^

Table 2 HSOPSC Subscales and Workplace Factor Categories

HSOPSC (2004) Subscales | Workplace Factor
1. Teamwork Within Units | 1. Teamwork
2. Supervisor/Manager Expectations & Actions Promoting Patient Safety | 2. Leadership
3. Organizational Learning—Continuous Improvement | 13. Innovation
4. Management Support for Patient Safety | 9. Organizational stability
5. Overall Perceptions of Patient Safety | No equivalent workplace factor
6. Feedback & Communication About Error | 2. Leadership
7. Communication Openness | 9. Organizational culture
8. Frequency of Events Reported | No equivalent workplace factor
9. Teamwork Across Units | 1. Teamwork
10. Staffing | 4. Staffing adequacy
11. Handoffs & Transitions | 1. Teamwork
12. Nonpunitive Response to Error | 9. Organizational stability or culture

Abbreviations. HSOPSC=Hospital Survey on Patient Safety Culture.

Table 3 PES-NWI Subscales and Workplace Factor Categories

PES-NWI Subscales | Workplace Factor
Nurse Participation in Hospital Affairs | 12. Participation in decision-making
Nursing Foundations for Quality of Care | No equivalent workplace factor
Nurse Manager Ability, Leadership, and Support of Nurses | 2. Leadership
Staffing and Resource Adequacy | 4. Staffing adequacy
Collegial Nurse–Physician Relations | 1. Teamwork

Abbreviations. PES-NWI=Practice Environment Scale of the Nursing Work Index.

The included KQ1a studies reported a mix of dichotomous outcomes and continuous outcomes. When it was reasonably concluded that dichotomous and continuous data measured a conceptually similar underlying construct, odds ratios were transformed to correlation coefficients via calculation of Cohen’s d.^29^ If measured constructs were not considered sufficiently conceptually similar, dichotomous and continuous effect data were separately synthesized. Correlation coefficients and standardized regression weights were combined to evaluate the association of nursing-related variables with quality of patient care.^30^ For analyses with few (k < 5) studies, we used the modified Knapp-Hartung approach^31^ to adjust the standard errors of the estimated coefficients. Otherwise, the Knapp-Hartung approach was used.^32^ Multivariate meta-analysis was used to aggregate studies with multiple outcome estimates. Meta-analyses were conducted using the metafor package for R (R Foundation for Statistical Computing, Vienna, Austria).^33^ We evaluated for statistical heterogeneity using visual inspection and use of 95% prediction intervals.

When quantitative synthesis was not feasible, we analyzed the data narratively. We gave more emphasis to the evidence from higher quality studies with more precise estimates of effect. Our narrative synthesis focused on documenting and identifying patterns in efficacy and safety of the interventions across conditions and outcome categories. We analyzed potential reasons for inconsistency in treatment effects across studies by evaluating differences in the study population, workplace factors, and outcome definitions.

For the studies sampled for qualitive meta-synthesis for KQ1b, we adapted rapid qualitative evidence synthesis methods coupled with qualitative thematic analysis using a mix of inductive and deductive codes of the findings from the primarily qualitative study data. We used richness scores and setting to prioritize studies for purposive sampling to maximize relevance and thematic saturation.^34,35^ Richness scores ranged from (1) very few qualitative data presented and those findings that are presented are fairly descriptive; (2) some qualitative data presented; (3) a reasonable amount of qualitative data; (4) a good amount and depth of qualitative data; (5) a large amount and depth of qualitative data. We prioritized abstracting all studies with a richness score of 4 or higher. When a health care setting (eg, acute care) was not represented by at least 1 study with a richness score of 4 or higher, we extracted and analyzed data from papers with lower richness scores to have representation in those health care settings.

For the studies included for KQ2, we mapped the workplace factors that the identified interventions aimed to impact and the safety or quality outcomes reported. We also categorized the setting and any frameworks or theories used to inform the intervention approach. As a map, we did not do any formal assessment of effectiveness.

### Strength of Evidence

The strength of evidence was assessed for KQ1a using the approach described by Grading of Recommendations Assessment, Development and Evaluation (GRADE).^36^ We limited GRADE ratings to those outcomes by workplace domain exposures identified by key VA stakeholders and the TEP as critical to decision-making for which we identified relevant studies (ie, leadership, nursing autonomy, staffing adequacy, teamwork). In brief, this approach requires assessment of 4 domains: risk of bias, consistency, directness, and precision. Additional domains to be used when appropriate are coherence, dose-response association, impact of plausible residual confounders, strength of association (magnitude of effect), and publication bias. These domains were considered qualitatively; a summary rating was assigned after discussion by 2 investigators as high, moderate, low, or very low strength of evidence.

For KQ1b, we assessed the certainty of evidence using the Confidence in the Evidence from Reviews of Qualitative Research (GRADE-CERQual).^37^ The CERQual approach requires assessment across 4 components: methodological limitations, coherence, adequacy of data, and relevance. We limited GRADE-CERQual ratings to domains identified by the stakeholders and TEP as critical to decision-making (ie, leadership, nursing autonomy, staffing adequacy, and teamwork) and selected themes within these domains with the greatest conceptual richness.

As a map of the relevant intervention literature, GRADE certainty of evidence was not assessed for KQ2.