# BACKGROUND

Quality and safety in the delivery of health care is of paramount importance. The National Academy of Medicine defines quality of care as care that is safe, effective, patient-centered, timely, efficient, and equitable.^1^ Higher quality of care is associated with a whole host of positive outcomes such as lower hospital mortality rates, shorter hospital length of stays, development of fewer complications, and reductions in the overall cost of care among hospitalized patients,^2,3^ as well as greater patient satisfaction with care.^4^ Within health care settings, nurses play a critical role in both delivering and evaluating quality of care. Nurses comprise the largest sector of health care professionals in the US with more than 3 million registered nurses (RNs).^5^ In some health care settings, such as hospitals, the nursing workforce delivers patient care 24 hours a day, 7 days a week, and 365 days a year. Other health care professionals rely upon these ever-present nurses to identify and communicate patient changes that warrant immediate attention. Thus, as frontline providers, nurse ratings of health care quality and patient safety represent an important metric of quality of care in hospital settings.^3,6^ Subsequently, nurse-rated quality of care has been used as an outcome measure for decades and is recognized globally by nurse researchers as a valid and reliable measure.^6^ Multiple studies have reported significant association between objective measures of health care quality and nurse-rated quality of care.^3,6,7^ The association of nurse-rated quality of care to both nurse and patient outcomes is also well established.^3,8^ Nurse ratings of quality of care in hospitals as excellent have been associated with lower levels of nurse burnout,^9^ staffing that reflects lower patient to nurse ratios,^10,11^ and lower odds of 30-day mortality for inpatients.^12^

There are many factors that contribute to nurse-rated quality and safety of care.^13^ A recent systematic review identified evidence-based recommendations to guide nursing interventions that enhance quality and safety in nursing care.^14^ The majority of these recommendations addressed nursing work environment factors such as staffing issues, leadership characteristics, safety culture, interprofessional and patient/family communication, and resource adequacy. The nursing work environment is comprised of multiple characteristics, including physical features, organizational structures and policies, interpersonal factors, and work culture,^15^ and it is conceptually distinct from personal characteristics of nurses (eg, nurse self-image, age) or work environment indicators (ie, outcomes of work environment), such as job satisfaction, turnover, absenteeism, or burnout.^16^

The historical context of studies that have been conducted to examine the associations between nursing work environment factors and quality of care or patient safety is extensive. Landmark studies in this field have been conducted across the last 3 decades. Aiken et al^17^ contributed one of the early studies identifying associations between nursing outcomes (eg, job dissatisfaction, burnout, intent to leave, etc), hospital work climate (eg, staffing adequacy, workforce management by administration, managerial support, etc) and nurse-assessed quality of care (eg, adverse events, care left undone, etc). In 2002, Aiken et al^18^ published a high impact study report that drew even greater attention to organizational factors, nurse outcomes, and patient outcomes. Subsequently, the Institute of Medicine published a report, Keeping Patients Safe: Transforming Nurse Work Environments,^19^ which highlighted the connection between nurse work environments and patient safety. Hospital Magnet designation from the American Nurses Credentialing Center (ANCC) represents an organizational commitment to provide work environments which support professional nursing practice. Nursing work environments in these health care organizations have been associated with higher quality of care.^20^

Thus, attention to the nursing work environment and nurse-rated quality of care and patient safety remain important areas of exploration for seeking ways to not only improve the quality of care experienced by patients but also buffer key nursing workforce indicators such as nurse burnout and job satisfaction.^21^

The Veterans Health Administration (VA) is the largest integrated health care system in the United States. The VA system serves over 9 million Veterans through approximately 1,380 health care facilities, which include 170 VA medical centers and 1,193 Community-Based Outpatient Clinics.^22^ The system also includes Community Living Centers (skilled nursing facilities), Domiciliaries, and Community-Based Veteran Centers. The nursing workforce is a key component of the VA health care systems across all these settings and is an important factor in health care quality and patient safety. As such, the VA Office of Nursing Services nominated an evidence synthesis study to examine nursing perceptions of quality of care. The purpose of this review is to synthesize the literature exploring the relationship between nurse work environment factors, nurse-perceived health care quality, and nurse-perceived patient safety. Findings will be used by the VA Office of Nursing Services to inform future data collection to monitor trends in VA nurse-rated quality of care, guide efforts to address nurse performance obstacles, and identify potential interventions to foster healthy nurse work environments to bolster the health and well-being of the VA nursing workforce and VA patients.