# Appendices

## SEARCH STRATEGIES

### MEDLINE (VIA OVID) EPUB AHEAD OF PRINT AND IN-PROCESS, IN-DATA-REVIEW & OTHER NON-INDEXED CITATIONS AND DAILY (2014–2024)

# | Search Statement | Results
1 | (((patient adj3 (harm* or safety)) or (safety adj3 (climate or culture* or environment* or management)) or ((health care or care) adj3 (quality or safety)) or (adverse adj3 event*)) adj3 (belief* or believe* or feel* or impression* or judg* or opinion* or perceive* or perception* or perspective* or rate* or rating* or report* or understand* or view*)).ti,ab,kf. | 58195
2 | exp Nurses/ or exp Nursing Staff, Hospital/ or (nurse or nurses or nursing or RN or RNs).ti,ab,kf. | 616349
3 | 1 and 2 | 3584
4 | exp Adolescent/ or exp Child/ or exp Infant/ or exp Pediatrics/ or (adolescen* or babies or baby or boy* or child* or girl* or infan* or juvenil* or minors or neonat* or neo-nat* or newborn* or new-born* or paediatric* or pediatric* or perinat* or preschool* or preteen* or puber* or pubescen* or school* or teen* or toddler* or underage* or youth*).ti,ab,kf. or (pediatric* or paediatric* or infan* or child* or adolescen* or young).jn,jw. | 5352912
5 | 3 not 4 | 3015
6 | limit 5 to yr=“2014-Current” | 2028
7 | limit 6 to English language | 1980
| Total | 1980
| Total after deduplication | 1974

Search date: 12/16/2024

### CINAHL ULTIMATE (EBSCO) (2014–2025)

# | Search Statement | Results
1 | TI ( (((patient N3 (harm* or safety)) or (safety N3 (climate or culture* or environment* or management)) or ((health care or care) N3 (quality or safety)) or (adverse N3 event*)) N3 (belief* or believe* or feel* or impression* or judg* or opinion* or perceive* or perception* or perspective* or rate* or rating* or report* or understand* or view*)) ) OR AB ( (((patient N3 (harm* or safety)) or (safety N3 (climate or culture* or environment* or management)) or ((health care or care) N3 (quality or safety)) or (adverse N3 event*)) N3 (belief* or believe* or feel* or impression* or judg* or opinion* or perceive* or perception* or perspective* or rate* or rating* or report* or understand* or view*)) ) | 26345
2 | (MH “Nurses+”) OR TI (nurse or nurses or nursing or RN or RNs ) OR AB ( nurse or nurses or nursing or RN or RNs) | 715687
3 | S1 AND S2 | 3930
4 | ( (MH “Adolescence+”) or (MH “Child+”) or (MH “Pediatrics+”) ) OR TI ( adolescen* or babies or baby or boy* or child* or girl* or infan* or juvenil* or minors or neonat* or neo-nat* or newborn* or new-born* or paediatric* or pediatric* or perinat* or preschool* or preteen* or puber* or pubescen* or school* or teen* or toddler* or underage* or youth* ) OR AB ( adolescen* or babies or baby or boy* or child* or girl* or infan* or juvenil* or minors or neonat* or neo-nat* or newborn* or new-born* or paediatric* or pediatric* or perinat* or preschool* or preteen* or puber* or pubescen* or school* or teen* or toddler* or underage* or youth* ) OR SO ( pediatric* or paediatric* or infan* or child* or adolescen* or young ) | 1689328
5 | S3 NOT S4 | 3378
6 | limit S5 to Publication Date: 20140101-20251231 | 2076
7 | limit S6 to English language | 1901
| Total | 1901
| Total after deduplication | 837

Search date: 12/16/2024

### SCOPUS (ELSEVIER) (2014-2025)

# | Search Statement | Results
1 | TITLE-ABS-KEY ((((patient W/3 (harm* OR safety)) OR (safety W/3 (climate OR culture* OR environment* OR management)) OR ((health care OR care) W/3 (quality OR safety)) OR (adverse W/3 event*)) W/3 (belief* OR believe* OR feel* OR impression* OR judg* OR opinion* OR perceive* OR perception* OR perspective* OR rate* OR rating* OR report* OR understand* OR view*))) | 78216
2 | TITLE-ABS-KEY(nurse or nurses or nursing or RN or RNs) | 1061367
3 | 1 and 2 | 5985
4 | (TITLE-ABS-KEY((adolescen* OR babies OR baby OR boy* OR child* OR girl* OR infan* OR juvenil* OR minors OR neonat* OR neo-nat* OR newborn* OR new-born* OR paediatric* OR pediatric* OR perinat* OR preschool* OR preteen* OR puber* OR pubescen* OR school* OR teen* OR toddler* OR underage* OR youth*)) OR SRCTITLE((pediatric* OR paediatric* OR infan* OR child* OR adolescen* OR young))) | 8420953
5 | 3 not 4 | 4691
6 | limit 5 to 2014-2025 | 3342
7 | limit 6 to English language | 3120
| Total | 3120
| Total after deduplication | 912

Search date: 12/16/2024