# ABBREVIATIONS TABLE

Abbreviation: Definition
CASP: Critical Appraisal Skills Programme
GRADE: Grading of Recommendations Assessment, Development and Evaluation
GRADE-CERQual: Confidence in the Evidence from Reviews of Qualitative Research
HSOPS: Hospital Survey on Patient Safety Culture
HWEAT: Health Work Environment Assessment Tool
IQR: Interquartile range
PES-NWI: Practice Environment Scale of the Nursing Work Index
OECD: Organisation for Economic Cooperation Development countries
COE: Certainty of evidence
ROB: Risk of bias
SRW: Standardized regression weight
VA: Veterans Association