# Supplementary Materials

- Study Characteristics
- KQ1a InterventionCharacteristic
- KQ1b InterventionCharacteristic
- List of Included Studies
- List of Excluded Studies
- Peer Review Feedback
- Factors and Outcomes Table
- CASP RoB
- NIH RoB
- KQ2 Mapping
- Forest plot data

## VA Related Documents

Supplementary Materials (XLSX)