# REFERENCES

1 Department of Veterans Affairs. FY 22 Budget Submission. https://www.va.gov/budget/docs/summary/fy2022VAbudgetVolumeIImedicalProgramsAndInformationTechnology.pdf. Accessed March 3, 2022.
2 Kaiser Family Foundation. Total Number of Residents in Certified Nursing Facilities. . Kaiser Family Foundation. https://www.kff.org/other/state-indicator/number-of-nursing-facility-residents/?currentTimeframe=0&sortModel=%7B%22colId%22:%22Location%22,%22sort%22:%22asc%22%7D. Published 2021. Accessed August 20, 2021.
3 Chidambaram P. Data Note: How migh Coronavirus Affect Residents in Nursing Facilities? Kaiser Family Foundation. https://www.kff.org/coronavirus-covid-19/issue-brief/data-note-how-might-coronavirus-affect-residents-in-nursing-facilities/. Published 2020. Accessed September 9, 2021.
4 Ness J, Ahmed A, Aronow WS. Demographics and payment characteristics of nursing home residents in the United States: a 23-year trend. J Gerontol A Biol Sci Med Sci. 2004;59(11):1213–1217.15602078
5 Khatutsky G OC, Wiener JM, Greene AM, Johnson R, Jessup EA, Vreeland E, Sengupta M, Caffrey C, HarrisKojetin L. Residential care communities and their residents in 2010: A national portrait. . Hyattsville, MD: National Center for Health Statistics 2016. https://www.cdc.gov/nchs/data/nsrcf/nsrcf_chartbook.pdf
6 Harrington C, Schnelle JF, McGregor M, Simmons SF. The Need for Higher Minimum Staffing Standards in U.S. Nursing Homes. Health Serv Insights. 2016;9:13–19.27103819
7 Unroe KT, Ouslander JG, Saliba D. Nursing Home Regulations Redefined: Implications for Providers. J Am Geriatr Soc. 2018;66(1):191–194.29155452
8 Nursing Staff in Hospitals and Nursing Homes: Is It Adequate? Washington (DC): National Academies Press (US); 1996.
9 Harrington C, Dellefield ME, Halifax E, Fleming ML, Bakerjian D. Appropriate Nurse Staffing Levels for U.S. Nursing Homes. Health Serv Insights. 2020;13.
10 SSA. Requirements for, and assuring quality of care in, skilled nursing facilities. Vol 42 U.S.C. §§1395i-3(b)(4)(C)(i), 1396r(b)(4)(C)(i)(II) , Medicare and Medicaid, respectively; 42 C.F.R. §483.30(b)(1)1987. https://www.ssa.gov/OP_Home/ssact/title18/1819.htm
11 Harrington C, Ross L, Chapman S, Halifax E, Spurlock B, Bakerjian D. Nurse Staffing and Coronavirus Infections in California Nursing Homes. Policy Polit Nurs Pract. 2020;21(3):174–186.32635838
12 Paek SC, Zhang NJ, Wan TT, Unruh LY, Meemon N. The Impact of State Nursing Home Staffing Standards on Nurse Staffing Levels. Med Care Res Rev. 2016;73(1):41–61.26174211
13 Geng F, Stevenson DG, Grabowski DC. Daily Nursing Home Staffing Levels Highly Variable, Often Below CMS Expectations. Health Aff (Millwood). 2019;38(7):1095–1100.31260368
14 Gourley G. Community Living Centers and State Veterans Homes. Defense Media Network. https://www.defensemedianetwork.com/stories/community-living-centers-state-veterans-homes/. Published 2018. Accessed December 7, 2021.
15 GAO. VA Nursing Home Care VA Has Opportunities to Enhance Its Oversight and Provide More Comprehensive Information on Its Website. Office USGA, ed2019. https://www.gao.gov/assets/710/700366.pdf
16 Kim H, Harrington C, Greene WH. Registered nurse staffing mix and quality of care in nursing homes: a longitudinal analysis. Gerontologist. 2009;49(1):81–90.19363006
17 Dellefield ME, Castle NG, McGilton KS, Spilsbury K. The Relationship Between Registered Nurses and Nursing Home Quality: An Integrative Review (2008-2014). Nursing economic$. 2015;33(2):95–116.26281280
18 Konetzka RT, Stearns SC, Park J. The staffing-outcomes relationship in nursing homes. Health Serv Res. 2008;43(3):1025–1042.18454779
19 Donabedian A. Evaluating the quality of medical care. Milbank Mem Fund Q. 1966;44(3):Suppl:166–206.
20 Joanna Briggs Institute. Checklist for Analytical Cross Sectional Studies. The University of Adelaide. JBI Critical Appraisal Tools Web site. https://jbi.global/critical-appraisal-tools. Published 2021. Accessed July 1, 2021.
21 Guyatt G, Oxman AD, Sultan S, . GRADE guidelines: 11. Making an overall rating of confidence in effect estimates for a single outcome and for all outcomes. J Clin Epidemiol. 2013;66(2):151–157.22542023
22 Iorio A, Spencer FA, Falavigna M, . Use of GRADE for assessment of evidence about prognosis: rating confidence in estimates of event rates in broad categories of patients. bmj. 2015;350.
23 Murad MH, Mustafa RA, Schunemann HJ, Sultan S, Santesso N. Rating the certainty in evidence in the absence of a single estimate of effect. Evid Based Med. 2017;22(3):85–87.28320705
24 White EM, Aiken LH, Sloane DM, McHugh MD. Nursing home work environment, care quality, registered nurse burnout and job dissatisfaction. Geriatr Nurs. 2020;41(2):158–164.31488333
25 Alexander GL. An analysis of nursing home quality measures and staffing. Qual Manag Health Care. 2008;17(3):242–251.18641507
26 Castle NG, Ferguson-Rome JC. Influence of Nurse Aide Absenteeism on Nursing Home Quality. Gerontologist. 2015;55(4):605–615.24398653
27 Lin H. Revisiting the relationship between nurse staffing and quality of care in nursing homes: An instrumental variables approach. Journal of Health Economics. 2014;37(1):13–24.24887707
28 Lee HY, Blegen MA, Harrington C. The effects of RN staffing hours on nursing home quality: a two-stage model. Int J Nurs Stud. 2014;51(3):409–417.24182619
29 Trinkoff AM, Han K, Storr CL, Lerner N, Johantgen M, Gartrell K. Turnover, staffing, skill mix, and resident outcomes in a national sample of US nursing homes. J Nurs Adm. 2013;43(12):630–636.24232236
30 Temkin-Greener H, Cai S, Zheng NT, Zhao H, Mukamel DB. Nursing home work environment and the risk of pressure ulcers and incontinence. Health Serv Res. 2012;47(3 Pt 1):1179–1200.22098384
31 Castle NG, Anderson RA. Caregiver staffing in nursing homes and their influence on quality of care: Using dynamic panel estimation methods. Medical Care. 2011;49(6):545–552.21577182
32 Flynn L, Liang Y, Dickson GL, Aiken LH. Effects of nursing practice environments on quality outcomes in nursing homes. J Am Geriatr Soc. 2010;58(12):2401–2406.21054327
33 Castle NG, Engberg J. The influence of staffing characteristics on quality of care in nursing homes. Health Serv Res. 2007;42(5):1822–1847.17850522
34 Bostick JE. Relationship of nursing personnel and nursing home care quality. J Nurs Care Qual. 2004;19(2):130–136.15077830
35 Castle NG, Lin M. Top management turnover and quality in nursing homes. Health Care Manage Rev. 2010;35(2):161–174.20234222
36 Castle NG, Engberg J. Further examination of the influence of caregiver staffing levels on nursing home quality. The Gerontologist. 2008;48(4):464–476.18728296
37 Bosco E, Zullo AR, McConeghy KW, . Long-term Care Facility Variation in the Incidence of Pneumonia and Influenza. Open Forum Infect Dis. 2019;6(6):ofz230.31214626
38 Castle N, Engberg JB, Wagner LM, Handler S. Resident and Facility Factors Associated With the Incidence of Urinary Tract Infections Identified in the Nursing Home Minimum Data Set. J Appl Gerontol. 2017;36(2):173–194.25948289
39 Li Y, Temkin-Greener H, Shan G, Cai X. COVID-19 Infections and Deaths among Connecticut Nursing Home Residents: Facility Correlates. Journal of the American Geriatrics Society. 2020;68(9):1899–1906.32557542
40 Uchida-Nakakoji M, Stone PW, Schmitt SK, Phibbs CS. Nurse workforce characteristics and infection risk in VA Community Living Centers: a longitudinal analysis. Med Care. 2015;53(3):261–267.25634087
41 Trivedi TK, DeSalvo T, Lee L, . Hospitalizations and mortality associated with norovirus outbreaks in nursing homes, 2009-2010. JAMA. 2012;308(16):1668–1675.23079758
42 Orth J, Li Y, Temkin-Greener H, Simning A, Zimmerman S. End-of-Life Care among Nursing Home Residents with Dementia Varies by Nursing Home and Market Characteristics. Journal of the American Medical Directors Association. 2021;22(2):320.32736989
43 Thomas KS, Rahman M, Mor V, Intrator O. Influence of hospital and nursing home quality on hospital readmissions. Am J Manag Care. 2014;20(11):e523–531.25730351
44 Xing J, Mukamel DB, Temkin-Greener H. Hospitalizations of nursing home residents in the last year of life: nursing home characteristics and variation in potentially avoidable hospitalizations. J Am Geriatr Soc. 2013;61(11):1900–1908.24219191
45 Ogunneye O, Rothberg M, Friderici J, . Nursing home care quality and 30-day readmission rates for patients with heart failure. Circulation: Cardiovascular Quality and Outcomes. 2012;5(3 SUPPL. 1).
46 O’Malley AJ, Caudry DJ, Grabowski DC. Predictors of nursing home residents’ time to hospitalization. Health Serv Res. 2011;46(1 Pt 1):82–104.20849556
47 Xu H, Bowblis JR, Caprio TV, Li Y, Intrator O. Nursing Home and Market Factors and Risk-Adjusted Hospitalization Rates Among Urban, Micropolitan, and Rural Nursing Homes. Journal of the American Medical Directors Association. 2021;22(5):1101–1106.33008755
48 Domi M, Leitson M, Gifford D, Nicolaou A, Sreenivas K, Bishnoi C. The BNT162b2 vaccine is associated with lower new COVID-19 cases in nursing home residents and staff. Journal of the American Geriatrics Society. 2021.
49 Gorges RJ, Konetzka RT. Staffing Levels and COVID-19 Cases and Outbreaks in U.S. Nursing Homes. J Am Geriatr Soc. 2020;68(11):2462–2466.32770832
50 Min A, Hong HC. Effect of nurse staffing on rehospitalizations and emergency department visits among short-stay nursing home residents: A Cross-sectional study using the US Nursing Home Compare database. Geriatric nursing (New York, NY). 2019;40(2):160–165.
51 Arling G, Kane RL, Mueller C, Bershadsky J, Degenholtz HB. Nursing effort and quality of care for nursing home residents. Gerontologist. 2007;47(5):672–682.17989409
52 Shippee TP, Hong H, Henning-Smith C, Kane RL. Longitudinal Changes in Nursing Home Resident-Reported Quality of Life: The Role of Facility Characteristics. Res Aging. 2015;37(6):555–580.25651583
53 Shin JH, Park T, Huh IS. Nursing Staffing and Quality of Life in Western New York Nursing Homes. West J Nurs Res. 2014;36(6):788–805.24258404
54 Abrahamson K, Lewis T, Perkins A, Clark D, Nazir A, Arling G. The influence of cognitive impairment, special care unit placement, and nursing facility characteristics on resident quality of life. J Aging Health. 2013;25(4):574–588.23511654
55 Castle NG. The influence of consistent assignment on nursing home deficiency citations. Gerontologist. 2011;51(6):750–760.22056960
56 Castle NG, Wagner LM, Ferguson-Rome JC, Men A, Handler SM. Nursing home deficiency citations for infection control. Am J Infect Control. 2011;39(4):263–269.21531271
57 Castle NG, Wagner LM, Ferguson JC, Handler SM. Nursing home deficiency citations for safety. J Aging Soc Policy. 2011;23(1):34–57.21207305
58 Lerner NB, Johantgen M, Trinkoff AM, Storr CL, Han K. Are nursing home survey deficiencies higher in facilities with greater staff turnover. J Am Med Dir Assoc. 2014;15(2):102–107.24139163
59 Temkin-Greener H, Zheng NT, Cai S, Zhao H, Mukamel DB. Nursing home environment and organizational performance: association with deficiency citations. Med Care. 2010;48(4):357–364.20220535
60 Bowblis JR, Crystal S, Lucas JA, Intrator O. Response to regulatory stringency: The case of antipsychotic medication use in nursing homes. Health Economics (United Kingdom). 2012;21(8):977–993.
61 Hefele J, Nadash P, Livingstone I, Barch D, Leland N. The Relationship Between Quality of Care, Physical Therapy, and Occupational Therapy Staffing Levels in Nursing Homes in 4 Years’ Follow-up. Journal of the American Medical Directors Association. 2019;20(4):462–469.30954134
62 Leland NE, Gozalo P, Teno J, Mor V. Falls in newly admitted nursing home residents: a national study. J Am Geriatr Soc. 2012;60(5):939–945.22587857
63 Warren RL, Wirtalla C, Jette DU. Rehabilitation in skilled nursing facilities: Effect of nursing staff level and therapy intensity on outcomes. American Journal of Physical Medicine and Rehabilitation. 2004;83(9):704–712.15314535
64 Tong PK. The effects of California minimum nurse staffing laws on nurse labor and patient mortality in skilled nursing facilities. Health Econ. 2011;20(7):802–816.20672247
65 McGarry BE, Gandhi AD, Grabowski DC, Barnett ML. Larger Nursing Home Staff Size Linked To Higher Number Of COVID-19 Cases In 2020. Health Aff (Millwood). 2021;40(8):1261–1269.34260313
66 Centers for Medicare and Medicaid Services. Staffing Data Submission Payroll Based Journal. https://www.cms.gov/Medicare/Quality-Initiatives-Patient-Assessment-Instruments/NursingHomeQualityInits/Staffing-Data-Submission-PBJ. Accessed 2022, March 3.
67 Armijo-Olivo S, Craig R, Corabian P, Guo B, Souri S, Tjosvold L. Nursing Staff Time and Care Quality in Long-Term Care Facilities: A Systematic Review. Gerontologist. 2020;60(3):e200–e217.31115444
68 Backhaus R, Verbeek H, van Rossum E, Capezuti E, Hamers JP. Nurse staffing impact on quality of care in nursing homes: a systematic review of longitudinal studies. J Am Med Dir Assoc. 2014;15(6):383–393.24529872
69 Clemens S, Wodchis W, McGilton K, McGrail K, McMahon M. The relationship between quality and staffing in long-term care: A systematic review of the literature 2008-2020. Int J Nurs Stud. 2021;122:104036.34419730
70 Department of Veterans Affairs Office of Inspector General. Review of VHA Community Living Centers and Corresponding Star Ratings. 2020. https://www.va.gov/oig/pubs/VAOIG-18-05113-81.pdf
71 Agha Z, Lofgren RP, VanRuiswyk JV, Layde PM. Are patients at Veterans Affairs medical centers sicker? A comparative analysis of health status and medical resource use. Arch Intern Med. 2000;160(21):3252–3257.11088086
72 Intrator O, O’Hanlon CE, Makineni R, Scott WJ, Saliba D. Comparing Post-Acute Populations and Care in Veterans Affairs and Community Nursing Homes. J Am Med Dir Assoc. 2021;22(12):2425–2431 e2427.34740562
73 Salary.com. www.salary.com. Accessed Deember 27, 2021.
74 Matthews K, Guenther S, McVay K, Brass G. THE BEHAVIORAL RECOVERY OUTREACH TEAM: CONTINUITY OF CARE FOR INDIVIDUALS WITH DEMENTIA. Innov Aging. 2017;1(Suppl 1):1350–1351.
75 Centers for Medicare and Medicaid Services. Nursing Home Staff Turnover and Weekend Staffing Levels. https://www.cms.gov/files/document/qso-22-08-nh.pdf. Accessed 2022, March 3.
76 Hemming K, Haines TP, Chilton PJ, Girling AJ, Lilford RJ. The stepped wedge cluster randomised trial: rationale, design, analysis, and reporting. BMJ. 2015;350:h391.25662947
77 Crawford S, Kapoor A, Fisher K, . The Association of Nursing Home Characteristics and Quality with Adverse Events After a Hospitalization. Journal of the American Medical Directors Association. 2021.
78 Shin JH. Relationship between nursing staffing and quality of life in nursing homes. Contemporary nurse. 2013;44(2):133–143.23869498
79 Bonner A, Rapp MP, Buri JB, Aigner MJ, Drew S, Phipps J. Nurse practitioner/physician collaborative models of care…Aigner MJ, Drew S, Phipps J. A comparative study of nursing home resident outcomes between care provided by nurse practitioners/physicians versus physicians only. JAMDA 2004;5:16-23. Journal of the American Medical Directors Association. 2004;5(3):219–221.15160733