# ACKNOWLEDGMENTS

The authors are grateful to Benjamin Stroebel for helping with abstract triage and full-text review, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Colleen Walsh-Irwin, DNP, RN, ANP-BC, AACC, FAANP
  Program Manager Evidence Based Practice
  Office of Nursing Services
- Sheila Cox Sullivan, PhD, RN
  Director of Research and Analytics
  Office of Nursing Services

## Technical Expert Panel

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Jim Rudolph, MD
  Associate Professor of Medicine, Brown University
  Director of Long-term Services and Support Center of Innovation
  Office of Geriatrics and Extended Care, Providence VA
- Rhonda Toms, MSN, BSN, RN-BC
  National Program Manager
  Office of Geriatrics and Extended Care
- Jenice Guzman-Clark, PhD, GNP-BC, FAMIA
  Nurse Scientist
  Office of Geriatrics and Extended Care, Southern Arizona VA Healthcare System
- Bob Meiches, MD, MBA
  Medical Director of Rehabilitation and Extended Care
  VISN 23
- Joseph Gaugler, PhD, MS
  Professor and Robert L. Kane Endowed Chair of Long-Term Care and Aging
  Director of Center for Aging and Innovation
  University of Minnesota

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence (see Appendix E for disposition of comments). Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center works to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.