# DISCUSSION

## SUMMARY OF KEY FINDINGS

In this review, we identified 44 eligible studies that addressed the effects of nurse staffing on processes of care and resident outcomes in nursing homes (KQ 1). We did not find any eligible studies that addressed KQ 2. All eligible studies were observational in design, and the vast majority used CMS datasets to assess processes of care or resident outcomes. Only 1 study focused on outcomes in VA CLCs; no studies compared outcomes across VA CLCs and non-VA community nursing homes. The most frequently addressed outcomes were pressure ulcers and nursing home-associated infections, with one-third of the latter group evaluating COVID-19. We evaluated overall certainty of evidence for 3 high-priority resident outcomes: pressure ulcers, infections, and moderate-severe pain in residents. Key findings include the following:

- Higher RN staffing is probably associated with fewer pressure ulcers among residents of nursing homes (moderate confidence); LPN and NA staffing may also be associated with fewer pressure ulcers (low confidence)
- Total nurse staffing is probably not associated with pressure ulcers in residents (moderate confidence), but higher skill mix may be associated with fewer pressure ulcers (low confidence)
- Higher RN and NA staffing, and higher skill mix may be associated with lower resident COVID-19 infection and mortality in nursing homes, while LPN staffing may not be associated with COVID-19 outcomes (low confidence for all findings)
- Higher RN staffing and skill mix may be associated with less UTI among nursing home residents, while LPN, NA, and total staffing may not be associated with rates of UTI (low confidence for all findings)
- Higher RN staffing and skill mix may be associated with lower rates of moderate-severe pain among nursing home residents (low confidence), but it is unclear if LPN, NA, and total staffing are associated with pain outcomes (very low confidence)
- Only 1-2 studies addressed effects of nurse staffing on use of antipsychotics medications, falls with major injury, discharge to community, and all-cause mortality
- Results for other resident outcomes and processes of care were largely inconsistent across studies, and sometimes within the same study

Since our initial search, another observational study evaluating COVID-19 outcomes in nursing homes was published; total nurse staffing and skill mix (RN and LPN to total staffing) were not associated with COVID-19 rates or mortality during June-September 2020.^65^ This study used CMS mandated data on COVID-19 infections for a national sample of nursing homes. Overall, results from this study did not substantially change our findings for COVID-19.

Nursing home administrators must determine the optimal nurse staffing that is financially feasible and maximizes resident outcomes. Resources needed to employ sufficient nursing staff must be balanced against needs in other areas, such as environmental safety and recreational services. We have found only observational studies that examined the relationship between nurse staffing and processes of care and resident outcomes. The use of CMS mandated data to study nursing home outcomes is powerful and practical, but presents several concerns. CMS data (eg, OSCAR/CASPER and MDS) were not collected for research purposes, but to meet federal requirements for nursing homes. As these data directly inform payment or ability to operate, and most are reported by nursing home staff, there may be under-reporting of certain outcomes and over-reporting of staffing levels. In 2016, CMS switched to PBJ for nurse staffing, which required that staffing data is based on payroll (or other auditable information).^66^ However, most eligible studies used CMS staffing data collected before implementation of PBJ. Additionally, in many studies, outcomes data were not clearly collected after nurse staffing data, which may also change over time. CMS data captures nurse staffing at a certain time or averaged over some time period. This presents challenges for understanding the potential impact of fluctuations in nurse staffing (eg, over intervening weeks or differences between weekdays and weekends). Timing of data collection is likely also not ideal for capturing rates of acute outcomes such as nursing home-associated infections. These methodological concerns limit the ability to detect true associations, and may contribute to counter-intuitive results, such as when insufficient nurse staffing leads to under-detection of pressure ulcers or pain among residents. Staffing assessment of patient-centered outcomes (eg, pain) may also substantially differ from resident or family reports. This concern has been addressed by changes in MDS 3.0 data collection (beginning in 2010) that now incorporate resident interviews, but none of the eligible studies examining these outcomes used MDS 3.0 data.

Notably, studies for 2 outcomes (COVID-19 infections and quality of life) often used data sources outside of these CMS datasets. COVID-19 studies used a variety of sources including state agency data and reports from news organizations to capture COVID-19 cases and mortality. However, these studies still used CMS data on nurse staffing, which are collected once a year; although studies selected the timepoint for staffing data before the time period when COVID-19 infections occurred, these studies would not have captured any fluctuations in staffing during the early stages of the pandemic. Several studies on quality of life used in-person interviews with nursing home residents, but these were limited to data for nursing homes in a single state.

Finally, variation across studies in analytic approaches, definitions of nurse staffing, and outcomes measures presented substantial challenges for interpretation and synthesis of results. Nurse staffing measures included separate effort or hours for RN, LPN, or NA, and also total nurse staffing or total licensed nursing (RN and LPN). Similarly, there was different measures of skill mix, with some focusing on RN effort or time. Because these staffing measures are related and these relationships may vary depending on state-level regulations regarding specific types of nurse staffing, the analytic approaches likely impacted whether individual studies may be able to detect separate effects due to RN, LPN, and NA staffing. Studies used a variety of analytic approaches, included mixed effects models and instrumental variables approaches. In particular, some studies evaluated data before and after policy changes regarding nursing home regulations, taking advantage of a natural experiment to evaluate the causal relationship between nurse staffing and resident outcomes. Past reviews of how nurse staffing affects resident outcomes have noted similar challenges in summarizing and interpreting the evidence from such observational studies; these have generally found mixed results across studies for a variety of outcomes with some limited evidence for better outcomes with higher staffing.^67–69^

There remain substantial challenges to observational analyses of the relationship between nurse staffing and resident outcomes. Nursing homes are complex, heterogenous environments. They are regulated by multiple federal, state, and other agencies. Even high-quality observational studies may not be able to account for all resident population and facility confounders. Nurse staffing may play a key role in resident outcomes, but they are not the only factor. Other providers (eg, physicians, physician extenders, and allied health professionals), the physical environment, and policies within a nursing home also affect resident outcomes. The number of these other factors and the complexity of how they interplay was detailed in conceptual models employed in multiple eligible studies. Data were generally not available for all of these confounding factors or often had substantial limitations in accuracy. Thus, it is generally difficult to separate causal effects of nurse staffing versus higher nurse staffing (or skill mix) as an indicator of generally positive environments or higher resources in nursing homes.

## IMPLICATIONS FOR VA POLICY

This review summarizes the evidence regarding the effects of nurse staffing on resident outcomes and processes of care. We found only 1 eligible study that evaluated these effects for VA CLCs. There are substantial concerns in generalizability of results from studies of non-VA US nursing homes to VA CLCs. VA CLC residents are likely very different from the average community nursing home resident. Federal law and VA policies require VA to treat any qualifying Veteran, regardless of ability to pay and especially if care needs reflect injuries or conditions related to past military service (ie, service-connected conditions). This requirement, along with being hospital-based facilities, likely lead to VA CLC residents having demographic differences, more health conditions and care needs, and overall greater acuity, compared with community nursing home residents.^70^ For example, most CLC residents are male, are younger, and have higher rates of certain conditions (eg, PTSD),^71,72^ compared with majority women and lower rates of mental health concerns in community nursing home residents. These differences may contribute to higher rates of certain outcomes (eg, pressure ulcers) in VA CLC residents.^70^ Furthermore, by VA policies, VA CLCs must have higher levels of nurse staffing (particularly RN staffing), compared to community nursing homes. For example, the single eligible study on VA CLCs showed that the average total nurse staffing was 4.6 HPRD, with 31% being RN staffing; this would be an average of 1.4 RN HPRD for each CLC. Community nursing homes generally had much less RN HPRD. Beyond staffing levels, there are likely other important differences in the nursing workforce and work environment between VA CLCs and community nursing homes. Therefore, the results regarding improved resident outcomes with higher RN staffing in community nursing homes may be less applicable to VA CLCs.

Aside from these concerns regarding applicability, larger environmental factors (eg, nursing shortages) may present substantial challenges to increasing nurse staffing. Nursing homes may also be less desirable employers compared with other facilities (eg, hospitals) that also need nursing staff, due to differences in salary and benefits, or other factors in the work environment. Additionally, our results suggest very small potential differences in resident outcomes associated with nurse staffing. For example, 1 study showed that 1 FTE higher of RN staffing per 100 residents reduced the rate of moderate-severe pain in residents by 0.5%^31^; this indicates that 2 additional FTE of RN staffing in a nursing home with 100 residents are needed to prevent 1 case of pain. Using a publicly available estimate of $75,000 for salary and benefits for RN,^73^ it would take $150,000 to prevent 1 resident from having moderate-severe pain. VA salaries for RNs are often higher, leading to even greater costs for VA.

Although outside the scope of this current review, VA CLCs may wish to consider changes beyond nurse staffing in order to improve specific resident outcomes. Other potential options include modifications to the nursing home environment and processes (eg, engaging all nurse staffing in care planning), and greater resources for other allied health professionals (eg, social workers and mental health staff). Some of these measures have been implemented by certain VA CLCs, including specialized teams to address mental health and behavioral symptoms among residents with dementia.^74^

## RESEARCH GAPS/FUTURE RESEARCH

We identified only 1 eligible study on nurse staffing and resident outcomes in VA CLCs; this focused on a composite outcome of pressure ulcers, pneumonia, and UTI. To better understand relationships between nurse staffing and other outcomes in VA CLCs, we recommend conducting additional studies using VA data and relevant study-specific assessments. Due to concerns noted above regarding applicability of results from non-VA community nursing homes, future studies should directly address these relationships for other outcomes in VA CLC residents.

Additionally, dedicated assessments of nurse staffing and resident outcomes in observational studies may provide a more accurate evaluation of the effects of nurse staffing. It would also be valuable to include data on organizational culture and other structural characteristics of nursing homes that are not usually reflected in CMS datasets. Although CMS has recently started to require reporting of nurse turnover and weekend nurse staffing,^75^ there remain many other aspects of staffing and work environment that are likely important for resident outcomes but not captured by CMS data.

Finally, all identified evidence regarding the effects of nurse staffing came from observational studies. Randomized trials of nurse staffing may be logistically challenging and also may engender substantial ethical concerns (eg, lowering nurse staffing below currently accepted levels may create unacceptable risks for resident safety). However, the complex relationships between nurse staffing, other nursing home facility characteristics, and resident factors make it very difficult to understand causal effects of nurse staffing from observational studies alone. One possible avenue to address these concerns may be to take an implementation science perspective, and consider whether certain study designs (eg, stepped wedge^76^) may be used to incorporate randomization in real-world setting and more rigorously examine the effects of nurse staffing. For example, a new initiative could offer more resources for nurse staffing to participating nursing homes, with different facilities randomly selected to increase staffing over different time periods. If such a study were conducted within an integrated regional or national health system, such as the VA, there may be additional opportunities to leverage existing infrastructure for resident health information that would provide more timely and accurate information than CMS datasets.

## LIMITATIONS

This evidence review has several limitations. The focus of this review was on nursing home staffing, and not on other organizational or structural factors of nursing homes that may be important for resident outcomes. We also limited results to resident outcomes and processes of care to those that were of interest to our stakeholders. Because our goal was to inform current policy and decision-making within the VA, we also limited eligibility to studies of US nursing homes using data from 2000 or later. Nursing homes are governed by a complex set of national (or more local) regulations, which have substantially changed since 2000 and may be very different for other countries. Training and experience for different types of nursing staff may also vary across different countries. There may also be differences in resident characteristics of non-US nursing homes, related to regulations and financial policies for nursing home benefits. Therefore, our results are likely not applicable to the effects of nurse staffing in non-US nursing homes.

## CONCLUSIONS

Evidence on nurse staffing and resident outcomes and processes of care come from observational studies. Higher RN staffing and skill mix were associated with fewer pressure ulcers, fewer nursing home-associated infections, and lower rates of moderate-severe pain. Effects of LPN, NA, and total staffing were mixed or unclear for these outcomes. Relationships between nurse staffing and a variety of other outcomes were inconsistent, or only evaluated by 1-2 studies. These findings may not generalize to VA CLCs, which have different resident characteristics and higher staffing levels than non-VA community nursing homes. More accurate and randomized study designs may be required to definitely evaluate the effects of nurse staffing on resident outcomes and processes of care.