# RESULTS

## OVERVIEW OF ELIGIBLE STUDIES

Of 9,152 unique titles and abstracts screened, 378 articles underwent full-text review (Figure 2). We identified 44 eligible studies after full-text review. A list of studies excluded at full-text review is provided in Appendix B. We also searched 14 websites for grey literature and identified 62 documents for potential inclusion. However, none were found to be eligible after evaluation by 2 reviewers. Most of these documents did not report new data on nurse staffing or resident outcomes; the few that provided data on these topics did not conduct analyses to examine the relationship between nurse staffing and outcomes.

Figure 2 Screening and Selection of Eligible Studies

The most commonly evaluated outcomes were pressure ulcers (k=15),^18,24–36^ nursing home-associated infections (k=13),^11,18,28,29,33,35,37–41^ hospitalizations (k=8),^24,37,42–47^ residents with moderate to severe pain (k=7),25,26,29,31,33,35,36 and urinary catheters (k=7)^26,28,29,31,33,35,36^ (Table 4). Fourteen eligible studies addressed multiple processes of care or resident outcomes of interest.^18,24–26,28,29,31,33–37,40,42^ None of the eligible studies addressed cost effectiveness (KQ2). Most studies used national US samples of nursing homes (k=21) and were cross-sectional (k=24). Only 1 study addressed nurse staffing and resident outcomes in VA CLCs.^40^ Ten included studies were high quality, 26 were moderate quality, and the remaining 8 were low quality (Table 4). Methodological concerns across many studies included: accuracy of outcomes and staffing data (most were reported by nursing home staff or administrators); timing of outcomes assessment with respect to staffing measures (eg, outcomes may have been assessed before data collection on staffing levels); and adequate consideration of confounders. From high- and moderate-quality studies, we abstracted detailed results on associations between nurse staffing and processes of care or resident outcomes. Detailed study characteristics and results for these studies are found in Appendix F.

First, we present results for key outcomes that were both high priority for our stakeholders and addressed by a sufficient number of studies: pressure ulcers, nursing home-associated infections, and pain (moderate to severe). We describe effects separately by different nurse staffing (eg, RN, LPN, or NA) or skill mix variables. We also present overall certainty of evidence for summary findings regarding these outcomes (using GRADE, see Methods). Then, we summarize results for the remaining outcomes.

Table 4 Summary Characteristics of Eligible Studies

Characteristics | # Studies by Quality
Characteristics | High; (k=10) | Moderate; (k=26) | Low; (k=8)
Study Design
Cross-sectional | 4 | 16 | 4
Longitudinal | 5 | 8 | 4
Repeated time series | 1 | 2 | —
Data Sources
CMS | 10 | 25 | 6
VA | 1 | — | —
Other federal sources | 1 | 7 | 2
State agencies | 3 | 14 | —
Infectious disease datasets | 2 | 1 | —
Other^*^ | 4 | 15 | 3
Settings
National US | 4 | 15 | 2
State-level:
≥10 States | 2 | — | —
<10 States | 4 | 12 | 6
Nurse Staffing Levels & Skill Mix
Nurse staffing was primary or secondary focus of study | 8 | 13 | NA
Independent variable(s):
Nurse staffing levels | 10 | 27 | 8
Skill mix | 5 | 9 | 4
Resident Outcomes & Processes of Care
Pressure ulcers | 1 | 11 | 3
Infections:
COVID-19 | 3 | 1 | —
Others^†^ | 2 | 4 | 2
Pain (moderate to severe) | — | 6 | 1
Urinary catheters | — | 7 | —
Functioning | 1 | 2 | 2
Quality of life | — | 3 | 1
Hospitalizations | 1 | 4 | 3
Citations for quality of care | 1 | 5 | 1
Antipsychotic use | — | 2 | —
Falls with major injury | 1 | 1 | —
Discharge to home or community | 1 | — | —
Mortality (all-cause) | — | 1 | —

Abbreviations. CMS=Centers for Medicare & Medicaid Services; NA=not abstracted; VA=Department of Veterans Affairs

* Company or corporation data, news organizations, American Hospital Association Database, independent surveys, direct observation, or time study

† Urinary tract infections, pneumonia, and norovirus

## PRESSURE ULCERS

One high-quality^18^ and 11 moderate-quality studies^26–33,35,36,42^ evaluated the association of pressure ulcers with nurse staffing levels (see Appendix Table F-1 for detailed results). Nine studies were cross-sectional^26,28–30,32,33,35,36,42^ and 3 were longitudinal analyses.^18,27,31^ Though all 12 studies used data derived from the Minimum Data Set (MDS), the outcome measures regarding pressure sores varied across studies. Pressure ulcers were primarily measured as prevalence among NH residents, but 1 study used the incidence of pressure ulcer within the past 14 days.^18^ One study specifically evaluated the number of residents with dementia who died with pressure ulcers (defined as having pressure ulcers on the last MDS before death).^42^ Most studies used data from years within 1999-2008. Six evaluated national samples of nursing homes, while the remaining used data from selected states. Sample sizes ranged from 63 to 14,618 nursing homes. Besides data from federal agencies and sources, 6 studies used state agency data^26–28,33,35,36^ and 7 used other data sources (eg, American Hospital Association data, or private company data).^26,30–33,35,36^ Five studies were conducted by the same research team led by Castle, GC.^26,31,33,35,36^

### RN Staffing

Higher RN staffing is probably associated with fewer pressure ulcers among residents of nursing homes (moderate confidence, Table 5). Among 11 studies addressing the relationship between RN staffing and pressure ulcers, 9 found that higher RN staffing was associated with fewer pressure ulcers.^18,26–28,31,33,35,36,42^ The remaining 2 studies found no association between RN staffing levels and the outcome of interest.^29,32^ Eight studies included conceptual models to inform their study design. Six studies conducted analyses adjusting for case mix and all studies adjusted for confounders such as environment, policy, and other staffing metrics. Five studies were conducted by Castle et al and all included conceptual models.^26,31,33,35,36^ The primary methodological limitation among all studies was uncertainty about whether measures of RN staffing had preceded assessment of the pressure ulcer outcomes. The magnitude of the association between RN staffing and pressure ulcers in nursing home residents is not clear.

### LPN Staffing

Higher LPN staffing may be associated with fewer pressure ulcers (low confidence, Table 5). Five moderate- and high-quality studies evaluated associations between LPN staffing and pressure ulcers.^31–33,35,36^ Four of these were from the same lead author (Castle, NG) and showed that higher LPN staffing was associated with fewer pressure ulcers.^31,33,35,36^ The fifth study found no association between measures of staffing and resident outcomes.^32^

### NA Staffing

Higher NA staffing may be associated with fewer pressure ulcers (low confidence, Table 5). Seven studies examined associations between NA staffing and pressure ulcers.^26,27,31–33,35,36^ Four of these found that higher NA staffing was associated with a decrease in pressure ulcer presence.^26,27,31,36^ The remaining 3 studies found no association between NA staffing levels and the outcome of interest.^32,33,35^

### Total Staffing

Total staffing is probably not associated with pressure ulcers in nursing home residents (moderate confidence, Table 5). Two studies of moderate quality evaluated total staffing and pressure ulcers in residents.^29,30^ One study was conducted in 162 facilities among high-risk patients,^30^ while the second study had a population size of 1,142 and was among all residents.^29^ The study by Temkin-Greener et al^30^ had a conceptual model and controlled for case/resident mix and other confounders of interest. It found no association between total staffing and the likelihood of pressure ulcers in the resident population (OR 1.11, p=0.62). The study by Trinkoff et al^29^ did not have a conceptual model and while it did control for other factors it did not control for case mix. As with Temkin-Greener et al, Trinkoff et al also did not find an association between total staffing and the presence of pressure ulcers (OR 1.01 [0.56, 1.82] among high-risk residents, OR 1.21 [0.58, 2.53] among low-risk residents).

### Nurse Skill Mix

Higher skill mix may be associated with fewer pressure ulcers among residents (low confidence, Table 5). Six studies evaluated skill mix as ratio of RN staffing to total staffing.^18,26,29,31,36,42^ Three of the studies included a conceptual model to inform their study and analytic design. Four of the studies included case mix as a confounder of interest, and all included other confounders such as environment, policy, and other staffing metrics in the models investigating the relationship between staff/skill mix and the outcome of interest. Three studies reported no association,^18,29,42^ and the other half of the studies reported an association between nurse skill mix and pressure ulcers.^26,31,36^

Table 5 Summary Findings for Pressure Ulcers in Nursing Home (NH) Residents

Staffing Measure or Skill Mix | Summary of Findings | Methodological Limitations | Indirectness | Imprecision | Inconsistency | Publication Bias | Overall Confidence
RN Staffing^18,26–29,31–33,35,36,42^ | Higher RN staffing is probably associated with less pressure ulcers (rates or likelihood) among NH residents | Serious^a^ | Not Serious | Not serious | Not Serious^b^ | Not Suspected | Moderate
LPN Staffing^31–33,45,46^ | Higher LPN staffing may be associated with less pressure ulcers (rates or likelihood) among NH residents | Serious^a^ | Not Serious | Not serious | Serious^c^ | Not Suspected | Low
NA Staffing^26,27,31–33,35,36^ | Higher NA staffing may be associated with less pressure ulcers (rates or likelihood) among NH residents | Serious^a^ | Not Serious | Not serious | Serious^d^ | Not Suspected | Low
Total Staffing^29,30^ | Total staffing is probably not associated with pressure ulcers among NH residents | Serious^a^ | Not Serious | Not serious | Not Serious | Not Suspected | Moderate
Skill Mix^18,26,29,31,36,42^ | Higher skill mix may be associated with less pressure ulcers (rates or likelihood) among NH residents | Serious^a^ | Not Serious | Not serious | Serious^e^ | Not Suspected | Low

Abbreviations. LPN = Licensed Practical Nurse; NA = Nursing Assistant; RN = Registered Nurse

a Pressure ulcers data relied on report by NH staff; most studies were cross-sectional; half or most of the results from studies conducted by the same lead author

b Nine of 11 studies found an association between RN staffing levels and a reduction in pressure ulcers among residents

c Four of the 5 studies were from the same lead author and all found an association; the 1 study not by the same author group found no association

d Three studies reported no association and the remaining 4 reported an association.

e Three studies reported no association and 3 reported an association

## NURSING HOME-ASSOCIATED INFECTIONS

Ten moderate- and high-quality studies examined nursing home associated infections.^11,18,28,29,35,39–41,48,49^ We first present results for COVID-19 outcomes, followed by other infections (eg, urinary tract infection [UTI]). See Appendix Table F-1 and Appendix Table F-2 for detailed study characteristics and results.

### COVID-19 Cases and Mortality

Three high-quality studies^11,48,49^ and 1 moderate-quality study^39^ evaluated the association between nurse staffing and COVID-19 cases and/or mortality. One study evaluated combined resident and staff COVID-19 deaths.^49^ Three studies were cross-sectional^11,39,49^ and 1 used repeated time series analyses.^48^ Two studies evaluated nursing homes within a single state,^11,39^ while 1 study looked at nursing homes in 17 states,^48^ and the fourth looked at national data.^49^ All 4 studies obtained staffing data from the CMS Payroll-Based Journal (PBJ), and controlled for the facility size.^11,39,48,49^ Three of these studies also accounted for the prevalence of COVID-19 in the local community.^39,48,49^ COVID-19 data were obtained from a variety of federal,^48,49^ state,^11,39^ county,^11^ and news organization sources.^11,39^ Methodological concerns for all of these studies were mainly regarding accuracy of data for COVID-19 outcomes reporting, timing of nursing home staffing data versus COVID-19 outcomes, and possible staff shortages due to COVID-19 outbreaks.

Across the 4 studies, RN HPRD ranged from 0.449 to 0.75. Total staffing was evaluated in 2 studies, with mean HPRD 3.9 in one,^11^ and 55% of nursing homes < 4.1 total nurse HPRD in the other.^11,49^ Only 1 study examined relationships between NA staffing (mean HPRD 2.3) or LPN staffing (mean HPRD 0.9) and COVID-19.^49^

#### RN Staffing

Higher RN staffing may be associated with lower resident COVID-19 infection and mortality (low confidence, Table 6). Four studies investigated the relationship between RN staffing and COVID-19 cases or mortality.^11,39,48,49^ The 2 state-level studies and 1 regional study all found that higher RN staffing was significantly associated with fewer COVID-19 cases and/or mortality.^11,39,48^ However, 1 national study found higher RN staffing was significantly associated with higher likelihood of nursing home having any COVID-19 cases (OR 1.34, p<0.01).^49^

#### LPN Staffing

LPN staffing may not be associated with COVID-19 infection or mortality (low confidence, Table 6). A single national study examined the relationship between LPN staffing and COVID-19 outcomes.^49^ It found no statistical association between LPN staffing and COVID-19 cases and low LPN staffing relative to medium LPN staffing was associated with fewer COVID-19 deaths. High LPN staffing relative to medium LPN staffing was not associated with COVID-19 mortality.

#### NA Staffing

Higher NA staffing may be associated with lower COVID-19 infection and mortality (low confidence, Table 6). The same national study described above also examined the relationship between NA staffing and COVID-19 outcomes.^49^ It found that among nursing homes with at least 1 COVID-19 case, those with high NA staffing (compared with middle tertile) had a lower likelihood of having an outbreak and fewer COVID-19 resident and staff deaths.

#### Total Staffing

It is unknown if total staffing is associated with COVID-19 infections or mortality (very low confidence, Table 6). One national study^49^ and 1 state-level study^11^ examined associations between total nurse staffing and COVID-19 outcomes. The national study found that nursing home with both low and high total staffing (compared to middle tertile) had fewer COVID-19 deaths. The state-level study found no association between nursing hours and COVID-19 cases.

#### Nurse Skill Mix

Higher nursing skill mix may be associated with higher resident COVID-19 infection (low confidence, Table 6). The same national study described above also examined the relationship between nurse skill mix COVID-19 outcomes.^49^ Skill mix was measured as RN to total nurse staffing. This study found that lower staff skill mix was significantly associated with lower likelihood of having any COVID-19 cases, while higher skill mix was associated with greater likelihood. The study found no association between staff skill mix and COVID-19 mortality.

### Other Infections

Six articles evaluated the association between nursing home staffing and infections.^18,28,29,35,40,41^ Four studies evaluated UTI,^18,28,29,35^ another study examined a composite measure of UTI, pneumonia, and pressure ulcers,^40^ and the sixth study addressed increased hospitalizations and mortality during norovirus outbreaks.^41^ Two of these were high quality and used longitudinal design,^18,40^ while 3 moderate-quality studies were cross-sectional^28,29,35^ and 1 moderate-quality study was also longitudinal.^41^ Two studies used an instrumental variable approach.^18,28^ One of these used the time a nursing home implemented the Medicare Prospective Payment System and percent of residents in a nursing home with Medicare as a payer source as the instrumental variables.^18^ The other study used the percent of the population over age 65 and the percent of females in the workforce as instrumental variables.^28^

One study focused specifically on VA CLCs, evaluating the composite measure noted above.^40^ Three studies focused on nursing homes in a single state^28^ or a small number of states.^18,41^ The remaining 2 studies focused on a national sample of US nursing homes.^29,35^ Staffing measures were obtained from study-specific survey data,^29,35^ OSCAR,^18,28^ or VA payroll data.^40^ Outcome data were obtained from the MDS,^18,28,29,40,41^ and Nursing Home Compare.^35^ Across these studies of non-VA US nursing homes, RN HPRD ranged from 0.1 to 0.6. In the VA CLC study, average total nurse staffing was 4.6 HPRD (SD 1.2), with 31% being RN, 26% LPN, and 42% NA.^40^

#### RN Staffing

Higher RN staffing may be associated with less UTI (proportion and likelihood) among residents (low confidence, Table 6). Three studies addressed the relationship between RN staffing and urinary tract infections.^18,28,35^ One high-quality study using instrumental variable approach found greater RN staffing was significantly associated with lower UTI.^18^ Another instrumental variable study of moderate quality found no significant association between RN staffing and UTI.^28^ A national study of moderate quality found that higher RN staffing was significantly associated with higher rates of UTI.^35^ Lower RN staffing may also be associated with worse outcomes (hospitalizations and mortality) for nursing home residents during norovirus outbreaks.^41^

#### LPN Staffing

LPN staffing may not be associated with UTI among nursing home residents (low confidence, Table 6). One study of national sample of nursing homes found no significant association between LPN staffing and rates of UTI.^35^

#### NA Staffing Level

Higher NA staffing may be associated with less UTI in residents (low confidence, Table 6). One national study of moderate quality found higher NA staffing was significantly associated with a decrease in the percent of residents with UTI.^35^

#### Total Staffing

Total staffing may not be associated with UTI (low confidence, Table 6). The study of VA CLCs found no significant association between total nurse HPRD and a composite measure of UTI, pneumonia, and pressure ulcers.^40^ A national study of non-VA US nursing homes categorized total nurse staffing as ≥ 5.0 HPRD or < 5.0 HPRD, with 88% being in the latter category.^29^ This study found no association between total staffing and UTI.

#### Nurse Skill Mix

Higher skill mix staffing may be associated with fewer UTI in nursing home residents (low confidence, Table 6). Three studies investigated the relationship between nurse skill mix and infections, and there was variation in the direction of effects across the studies.^18,29,40^ One study of national sample of nursing homes defined skill mix as total licensed nurse FTE (RN and LPN) to total nurse staffing, finding that it was not significantly associated with UTI.^29^ One study examining nursing homes from multiple states and using an instrumental variable approach found that higher skill mix (RN to total) was associated with fewer UTI.^18^ The VA CLC study examined both percent RN staffing (of total) and percent NA staffing; it found no significant associations between either and the composite outcome of UTI, pneumonia, and pressure ulcers.^40^

Table 6 Summary Findings for Nursing Home (NH) Associated Infections

Staffing Measure or Skill Mix | Summary of Findings | Methodological Limitations | Indirectness | Imprecision | Inconsistency | Publication Bias | Overall Confidence
COVID-19 Cases and Mortality
RN Staffing^11,39,48,49^ | Higher RN staffing may be associated with lower COVID infection and mortality (likelihood and rates). | Serious^a^ | Not Serious | Serious, borderline^b^ | Serious^c^ | Not Suspected | Low
LPN Staffing^49^ | Higher LPN staffing may not be associated with lower resident COVID infection (likelihood) and mortality (count). | Serious^a^ | Not Serious | Not Serious | — | Not Suspected | Low
NA Staffing^49^ | Higher NA staffing may be associated with lower resident COVID infection (likelihood) and mortality (count). | Serious^a^ | Not Serious | Not Serious | — | Not Suspected | Low
Total Staffing^11,49^ | It is unknown if total staffing is associated with resident COVID infection or mortality. | Serious^a^ | Not Serious | Serious, borderline^b^ | Serious^d^ | Not Suspected | Very Low
Skill Mix^49^ | Higher nursing skill mix may be associated with higher resident COVID infection (likelihood). | Serious^a^ | Not Serious | Not Serious | — | Not Suspected | Low
Other Infections
RN^18,28,35^ | Higher RN staffing may be associated with less UTI (likelihood and rates) among NH residents. | Serious^e^ | Not Serious | Not Serious | Serious, borderline^f^ | Not Suspected | Low
LPN^35^ | LPN staffing may not be associated with rates of UTI among NH residents. | Serious^e^ | Not Serious | Not serious | — | Not Suspected | Low
NA^29,35^ | Higher NA staffing may be associated with fewer UTI among NH residents. | Serious^e^ | Not Serious | Not serious | — | Not Suspected | Low
Total Staffing^50^ | Total staffing may not be associated with UTI (rates and likelihood). | Serious^e^ | Not Serious, borderline^g^ | Not serious | Not Serious | Not Suspected | Low
Skill Mix^18,29,40^ | Higher nursing skill mix may be associated with fewer UTI among NH residents. | Serious^e^ | Not Serious, borderline^g^ | Not serious | Serious, borderline^h^ | Not Suspected | Low

Abbreviations. LPN=Licensed practical nurse; NA=Nursing assistant; RN=Registered nurse UTI=urinary tract infection.

a Concerns due to accuracy of COVID-19 data, timing of nursing home staffing data vs COVID-19 outcomes, and possible staff shortages due to COVID-19 outbreaks.

b Wide confidence intervals for some effect estimates.

c Three studies found significant associations, while 1 study found opposite effect (higher RN staffing was associated with higher likelihood of COVID-19).

d One study found no significant associations and the other study showed that both low and high total staffing (compared with middle tertile) were associated with higher COVID-19 mortality.

e Cross-sectional studies with outcomes reported by NH staff.

f Two studies showed significant associations, and 1 did not find significant association.

g One study used composite outcome of UTI, pneumonia, and pressure ulcers.

h Variable definitions of skill mix, with 1 study finding significant association and 2 studies not finding significant associations.

## PAIN (MODERATE-SEVERE)

Six moderate-quality studies examined associations between nurse staffing and moderate-severe pain in nursing home residents, all using MDS 2.0 data for outcomes.^26,29,31,33,35,36^ MDS 2.0 data on residents with moderate-severe pain relied on reports by nursing home staff (beginning in 2010, pain outcomes in MDS 3.0 have been assessed by resident interviews). Five studies used data for national nursing home samples,^26,29,31,35,36^ and 1 study evaluated nursing homes in 6 states (Missouri, Texas, Pennsylvania, New York, Connecticut, and New Jersey).^33^ Summary of findings with certainty of evidence are shown in Table 7. See Appendix Table F-3 for detailed study characteristics and results.

### RN, LPN, and NA Staffing

Five studies evaluated associations between nurse staffing (measured as RN, LPN, or NA FTE per 100 residents) and rates of residents with moderate-severe pain.^26,31,33,35,36^ All 5 studies were conducted by the same lead author, and all used study-specific surveys of nursing home administrators to assess nurse staffing. Across these studies, NA FTE made up more than half of total nurse staffing, ranging from 26-33 FTE per 100 residents. RN staffing ranged from 12-15 FTE and LPN staffing was 11-17 FTE.

Higher RN staffing may be associated with lower rates of moderate-severe pain among nursing home residents (low confidence). Significant results were reported by 3 studies^31,35,36^; for example, 1 of these found 0.5% less residents with moderate-severe pain (per nursing home) for every 1 FTE higher RN staffing (per 100 residents).^31^ However, 2 studies did not find significant associations between RN staffing and rates of moderate-severe pain in residents.^26,33^

It was unclear if LPN and NA staffing were also associated with rates of moderate-severe pain among residents (very low confidence for both). Two studies reported that higher LPN and NA staffing were both associated with lower rates of moderate-severe pain among long-stay patients.^26,31^ One study found that higher LPN and NA FTE (per 100 residents) were each associated with higher rates of moderate-severe pain in long-stay residents but lower rates in short-stay residents.^35^ One study found no significant associations for either LPN or NA staffing.^33^ One study reported that higher NA FTE was associated with lower rates of moderate-severe pain in both long-stay and short-stay residents.^36^ This same study reported that LPN staffing had no significant association with moderate-severe pain in long-stay residents but did have significant associations with lower rates in short-stay residents.^36^

### Total Staffing

It was unclear if total nurse staffing is associated with moderate-severe pain in nursing home residents (very low confidence). One study examined data for a national nursing home sample to evaluate association between total nurse staffing (RN, LPN, and NA; dichotomized at < or ≥ 5.0 HPRD) and likelihood of NH being in the highest 75^th^ percentile for rates of residents with moderate to severe pain.^29^ The main variables of interest were NA and licensed nurse (RN and LPN) turnover rates, analyzed in separate models. In both models, total staffing was not significantly associated with the nursing home being in the top quartile for highest rates of residents with moderate to severe pain. This study did not report whether long-stay or short-stay residents (or both) were included in assessment of pain outcomes.

### Nurse Skill Mix

Higher skill mix may be associated with lower rates of moderate-severe pain among nursing home residents (low confidence). Four studies evaluated associations between skill mix and rates of moderate-severe pain.^26,29,31,36^ Three studies were conducted by the same lead author, defined skill mix as the ratio of RN FTE to total non-RN FTE (LPN and NA), and found that higher ratios were associated with lower rates of moderate-severe pain among long-stay residents.^26,31,36^ For example, 1 of these studies reported that 1% higher RN ratio was associated with 0.2% lower rates of moderate-severe pain.^31^ One of these studies also evaluated moderate-severe pain among short-stay residents but found no significant association with skill mix.^36^ Finally, 1 study evaluated association between skill mix and likelihood of the nursing home being in highest 75^th^ percentile for residents with moderate-severe pain.^29^ This study measured skill mix as a ratio of total licensed nurse staffing (RN and LPN) to total direct care staffing (RN, LPN, and NA), and reported no significant association.^29^

Table 7 Summary Findings for Pain (Moderate to Severe) in Nursing Home Residents

Staffing Measure or Skill Mix | Summary of Findings | Methodological Limitations | Indirectness | Imprecision | Inconsistency | Publication Bias | Overall Confidence
RN Staffing^26,31,33,35,36^ | Higher RN staffing may be associated with lower rates of moderate-severe pain among NH residents | Serious^a^ | Not serious | Not serious | Not serious, borderline^b^ | Not Suspected | Low
LPN Staffing^26,31,33,35,36^ | Unknown if LPN staffing is associated with rates of moderate-severe pain among NH residents. | Serious^a^ | Not serious | Not serious | Serious^c^ | Not Suspected | Very Low
NA Staffing^26,31,33,35,36^ | Unknown if NA staffing is associated with rates of moderate-severe pain among NH residents | Serious^a^ | Not serious | Not serious | Serious^d^ | Not Suspected | Very Low
Total Staffing^29^ | Unknown if total staffing is associated with rates in moderate-severe pain among NH residents. | Serious^a^ | Not serious | Not serious, borderline^e^ | — | Not Suspected | Very Low
Skill Mix^26,29,31,36^ | Higher nursing skill mix may be associated with lower rates of moderate-severe pain among NH residents | Serious^a^ | Not serious | Not serious | Not serious, borderline^b^ | Not Suspected | Low

Abbreviations. LPN=Licensed practical nurse; NA=Nursing assistant; RN=Registered nurse

a Pain outcomes reported by NH staff; most cross-sectional studies; all or most results from studies conducted by same lead author

b No significant association in 2 studies

c Association with lower rates in 2 studies, no significant association in 1 study, significant association only with lower rates for short-stay residents in 1 study, and both higher and lower rates (for long and short-stay patient outcomes, respectively) in 1 study.

d Association with lower rates in 3 studies, no significant association in 1 study, and both higher and lower rates (for long and short-stay patient outcomes, respectively) in 1 study.

e Wide confidence intervals

## URINARY CATHETERS

Seven studies addressed the use of urinary catheters and all used MDS data for outcome data (see Appendix Table F-1 for detailed results).^26,28,29,31,33,35,36^ All were moderate quality and conducted between 2000 and 2008. Five of the studies were from the same research group, Castle et al.^26,31,33,35,36^ Six of the studies were cross-sectional, while the seventh used a longitudinal design.^31^ Five studies evaluated data for national samples of nursing homes,^26,29,31,35,36^ 1 looked at nursing homes only in Colorado,^28^ and the seventh examined nursing homes in 6 states (Missouri, Texas, Pennsylvania, New York, Connecticut, and New Jersey).^33^

There is inconsistency in the relationship between nurse staffing and use of urinary catheters in nursing homes, with some studies finding significant associations and others finding none. All 7 addressed RN staffing levels, 5 evaluated LPN and NA staffing levels,^26,31,33,35,36^ and 3 examined skill mix.^26,29,31^ None of the studies addressed total nurse staffing. Four studies showed a significant association between higher RN staffing and lower use of catheters,^26,29,31,33^ while the other 3 studies found no significant associations.^28,35,36^ Four studies found a significant association between higher NA staffing and lower catheter use,^26,31,35,36^ and 1 study found no association.^33^ Two studies showed a significant association between higher skill mix and lower catheter use,^26,31^ while the third study found no association.^29^

## FUNCTIONING

Three studies addressed functioning in nursing home residents and all used MDS data on worsening in activities of daily living (ADL, including bed mobility, transfer, eating, and toileting) or basic mobility (able to move around the room).^33,35,51^ See Appendix Table F-3 for detailed results. One high-quality study measured nurse staffing hours by observation and detailed self-reports from staff at 105 nursing homes in 4 states (Colorado, Indiana, Mississippi, and Minnesota), specifying resident-specific time (attributed by staff to individual residents) out of total direct care HPRD by RN, LPN, or NA.^51^ Higher total RN HPRD was associated with lower likelihood of decline in ADL at 90 days (coefficient −0.27, OR 0.76, p<0.05), but LPN HPRD was associated with higher likelihood of decline (coefficient 0.25, OR 1.28, p<0.05); NA HPRD did not have significant association (coefficient not reported). Higher resident-specific time was associated with greater likelihood of ADL decline for RN (coefficient 0.09, OR 1.09, p<0.05), LPN (coefficient 0.13, OR 1.14, p<0.05), and NA (coefficient 0.42, OR 1.52, p<0.001). Notably, baseline data for ADL came from the MDS assessments closest to the time period during which nurse staffing hours were assessed; there was substantial variation in the gap between MDS assessment and nurse staffing measurement (mean 0.2 days, SD 24.2 days).

The 2 remaining moderate-quality studies were conducted by the same group and both examined worsening ADL and mobility.^33,35^ One study evaluated a national sample of 2,840 nursing homes, finding that higher RN, LPN, and NA staffing were all associated with lower proportions of residents with ADL decline (coefficients −0.06 to −0.09, p≤0.05).^35^ For mobility, higher RN and LPN staffing were associated with lower proportion of residents with decline (coefficients −0.06 and −0.05, p≤0.05), but NA staffing was associated with higher proportion with decline (coefficient 0.27, p≤0.05). The other study examined data for 1,071 nursing homes from 6 states (Missouri, Texas, Pennsylvania, New York, Connecticut, and New Jersey), showing that higher RN staffing, modeled as log(FTE per 100 residents), was associated with lower proportions of residents with declines in ADL (coefficient 0.76, p<0.01) and mobility (coefficient 0.83, p<0.01).^33^ LPN and NA staffing were not significantly associated with declines in ADL or mobility.

## QUALITY OF LIFE

Three moderate-quality studies reported on the association between nurse staffing and quality of life (see Appendix Table F-4 for detailed results).^52–54^ Two studies both examined outcomes for Minnesota nursing homes, using the Minnesota Department of Human Services data on nurse staffing and in-person interviews with a random sample of residents to assess quality of life.^52,54^ These state-wide interviews used a validated multi-domain instrument to measure resident quality of life and satisfaction with care.^52,54^ One study found that higher RN HPRD was associated with higher summary quality-of-life scores, but LPN and NA HPRD were not associated with differences in quality of life.^52^ The other study found that higher NA HPRD was associated with higher composite quality of life scores, but RN and LPN HPRD were not associated with these scores.^54^ Both studies adjusted for resident case mix.^52,54^

The third study evaluated outcomes for a small number of nursing homes in western New York State.^53^ This study used OSCAR data on nurse staffing and interviewed residents to assess quality of life; nurse staffing levels and skill mix were not associated with summary scores for quality of life.^53^

## HOSPITALIZATIONS

One high-quality^46^ and 4 moderate-quality studies^42–44,47^ evaluated hospitalizations (see Appendix Table F-5 for detailed results). Three studies were longitudinal,^44,46,47^ and the remaining 2 were cross-sectional.^42,43^ Four studies evaluated national samples of nursing homes, using CMS claims data to determine hospitalizations for nursing home residents.^42–44,47^ The fifth study used state agency data on hospitalizations for nursing homes in New York.^46^ Two studies focused specifically on potentially avoidable hospitalizations (PAH) among nursing home residents before death (within 90 days^42^ or within 1 year^44^).

Three studies evaluated effects of total nurse staffing levels, with 2 showing no associations with PAH within 90 days of death^42^ or overall hospitalization rates.^47^ The third study showed a significant association between higher total staffing and a slightly lower odds of PAH within 1 year of death (OR 0.94 [0.90, 0.99], p=0.02).^44^ Two studies examined effects of RN staffing; 1 showed that higher RN staffing was associated with a small decrease in probability of 30-day readmissions,^43^ and the other did not find significant associations between RN staffing and time to first hospitalization (or time between repeat hospitalizations).^46^ Only 1 study examined LPN and NA staffing and found no associations between these staffing levels and probability of 30-day readmission.^43^ Three studies evaluated skill mix and all 3 found an association between higher skill mix and fewer hospitalizations.^42,44,47^

## DEFICIENCY CITATIONS FOR QUALITY OF CARE

Five studies addressed associations between nurse staffing and citations for a range of deficiencies (see Appendix Table F-6 for detailed results). In all studies, deficiency citations were assessed using OSCAR data. Four studies included national samples of nursing homes,^55–58^ while 1 study focused on nursing homes in New York.^59^ One was high quality,^57^ and the remaining 4 were moderate quality.^55,56,58,59^ Three studies were conducted by the same group, used national samples of nursing homes, and evaluated separate associations with RN, LPN, and NA staffing.^55–57^ One of these examined odds of nursing homes having a specific citation for infection control and hand hygiene, finding that higher RN, LPN, and NA staffing were all associated with somewhat lower odds of having a citation (OR 0.89-0.91, p<0.05 or p<0.001).^56^ The other 2 studies examined counts of^55^ or odds of having any citation^57^ out of a number of different citations on quality of care. One of these found no association with nurse staffing (OR 0.77-1.01 for RN, LPN, and NA; p>0.05 for all),^55^ and the other found lower likelihood of citations with higher RN staffing (OR 0.95, p<0.01) but higher likelihood with higher LPN staffing (OR 1.02, p<0.05), and no association with NA staffing (OR 1.01, p>0.05).^57^

The fourth national study examined associations between total nurse staffing (RN, LPN, and NA; dichotomized at <5.0 or ≥5.0 HPRD) and the likelihood of being in the highest 75% percentile in number of citations (out of the set of citations for quality of care), finding no significant association (OR 1.03, 95% CI [0.63, 1.69]).^58^ This study also evaluated association with skill mix, measured as proportion of licensed nurse staffing (RN and LPN) out of total nurse staffing; there was no significant association (OR 0.99, 95% CI [0.97,1.01]).

The final study evaluated associations between nurse staffing (RN, LPN, or NA) and receiving citations for quality of care for 162 nursing homes in New York.^59^ Only higher RN staffing was associated with nursing homes having lower counts of citations (coefficient −0.25, p=0.005); there were no significant associations for LPN or NA staffing. This study also examined associations with likelihood of receiving more serious quality of care citations, but found no significant effects for any nurse staffing variable.

## OTHER OUTCOMES

Only 1-2 high- and moderate-quality studies addressed each of the following outcomes: use of antipsychotic medications,^28,60^ falls with major injury,^61,62^ discharge to home or community,^63^ and all-cause mortality.^64^ See Appendix Table F-7 for detailed results regarding these outcomes.

### Antipsychotic Use

Two eligible studies reported on associations between nurse staffing and antipsychotic medications use in nursing homes.^28,60^ Both were rated moderate quality and used OSCAR and Medicaid data. One study was cross-sectional and examined nursing homes in Colorado.^28^ This study used least squares regression modeling and found there was no significant association between RN HPRD and antipsychotic drug use.^28^ The second study was a repeated time series analysis using data from a national sample of nursing homes.^60^ Using mixed effects linear models, this study found no significant association between RN HPRD and antipsychotic medications.^60^ This study did find that higher LPN and NA HPRD were associated with slightly higher rates of antipsychotics use (coefficients 0.1-0.3, p<0.05).^60^

### Falls with Major Injury

One high-quality^62^ and 1 moderate-quality study^61^ evaluated the association between nurse staffing and resident falls. The high-quality study was cross-sectional and the moderate-quality study used a repeated time series design. Both studies evaluated national samples of nursing homes, and used data on nurse staffing from CASPER/OSCAR and falls outcomes from Nursing Home Compare (NHC) or MDS.^61,62^ These 2 studies found inconsistent results regarding nurse staffing and residents experiencing falls. Livingstone et al^61^ found that higher RN HPRD, but not LPN or NA, was associated with a statistically significant lower proportion of nursing home residents that had a fall. In contrast, Leland^62^ found higher NA HPRD, but not licensed nurses (RN and LPN), was associated with significantly lower resident falls. Neither study evaluated associations between nurse skill mix and resident falls. Inconsistent results between these 2 studies may have been due to their different primary goals; 1 was focused on evaluating the relationship between occupational and physical therapy staffing and resident outcomes (with nurse staffing included as covariates),^61^ whereas the other aimed to address organizational factors of nursing homes that included nurse staffing.^62^

### Discharge to Home or Community

One high-quality study reported on the association between nurse staffing and discharge to the community.^63^ This study evaluated 68 nursing homes who had contracted with a private company (SeniorMetrix) that assists facilities with quality improvement for their residents with Medicare Advantage. This cross-sectional study only evaluated outcomes for residents who had lengths of stay that were 100 days or shorter and used discharge data from the private company. Total nurse staffing was dichotomized at < 3.5 HPRD (34% of nursing homes) or ≥ 3.5 HPRD (66%). This study reported that residents in nursing homes with ≥ 3.5 HPRD were more likely to be discharged to the community (OR 1.53 [1.29–1.80]).

### Mortality

One moderate-quality study evaluated the association between nurse staffing and rates of nursing home residents who died.^64^ This longitudinal study examined 612 California nursing homes who had less total nurse staffing than was mandated by new state regulations in 2000 (3.2 HPRD). Using an instrumental approach based on the difference between actual nurse staffing (during years before the mandate) and 3.2, this study showed that higher total nursing per HPRD was associated with 6 fewer resident deaths.^64^