# METHODS

## TOPIC DEVELOPMENT

We worked with our representatives from the VA Office of Nursing Services and our Technical Expert Panel (TEP) to refine the review scope and develop the key questions (KQ). We developed a conceptual framework based on the Donabedian model for evaluating outcomes and quality of care provided by healthcare systems and facilities.^19^ The Donabedian model consists of 3 connected components: 1) Structure as organizational characteristics associated with the delivery of care (eg, number of nurses); 2) processes of care are what happens for the patient or resident (eg, prescribed antibiotics); and 3) outcomes measures that capture the effect of care on patient health or other metrics that are meaningful to the patient. In this review, we conceptualized that the structure of care in nursing homes includes nurse staffing levels and skill mix as important characteristics; these in turn impact processes of care (eg, use of antipsychotic medications and urinary catheters), which then impact resident outcomes (eg, nursing home-associated infections, pain severity, and quality of life) (Figure 1). We also considered that resident characteristics are likely to impact both processes of care and resident outcomes. Nurse staffing levels include care provided by different types of nursing staff (Table 1), as well as total care provided by all nursing staff. Nurse skill mix refers to the proportions or ratios between different types of nurses (eg, RN to total staffing).

Figure 1 Conceptual Framework

Table 1 Nursing Staff Characteristics and Responsibilities

Nursing Title | Education & Training Requirements | Responsibilities
Nursing Assistants (NA) | - May need to complete a state-approved education program and pass their states’ competency exam to become licensed or certified | - Provide basic care; - Help patients with activities of daily living
Licensed Practical or Vocational Nurses (LPN) | - Must complete a state-approved educational program, which typically takes about 1 year; - Must be licensed | - Provide basic nursing care
Registered Nurse (RN) | - May take different educational paths, such as bachelor’s degree in nursing, or associate’s degree in nursing with additional training; - Must be licensed | - Provide and coordinate patient care

* source: https://www.bls.gov/ooh/healthcare/home.htm

## KEY QUESTIONS (KQ)

KQ1 What are the effects of nursing home nurse staffing levels and staff mix on:
  a) Processes of care in nursing homes (eg, use of antipsychotics)?
  b) Resident outcomes in nursing homes (eg, falls)?
KQ2 Which nurse staffing levels and staff mix have demonstrated cost-effectiveness for improving resident outcomes?

## PROTOCOL

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (http://www.crd.york.ac.uk/PROSPERO/; registration number CRD42021266319.

## DATA SOURCES AND SEARCHES

We searched for peer-reviewed English-language articles from January 2000 to May 2021 in the following databases: MEDLINE, Embase, CINAHL, and the Cochrane Database of Systematic Reviews. We used Medical Subject Headings (MeSH) and title/abstract terms for nurse staffing (Table 1) and nursing homes (Appendix A). We also hand-searched bibliographies of relevant systematic reviews, identified from searches of the above databases, VA ESP, and AHRQ Evidence-based Practice Centers.

To supplement findings from the peer-reviewed literature, we also conducted a search of the grey literature. We developed a list of websites with input from our TEP and used key words to search these websites for relevant white papers pertaining to effects of nurse staffing on processes of care and resident outcomes in nursing homes. Websites searched included those for federal government agencies (eg, CMS, Centers for Disease Control and Prevention [CDC]), and professional organizations (eg, American Nurses Association); the full list of websites is provided in Appendix A. One reviewer conducted searches of websites and compiled a list of records for potentially relevant documents; these records were then screened by another reviewer to assess relevance and possible inclusion in the review. Documents included by the second reviewer were pulled and examined by a third reviewer for final determination of inclusion.

## STUDY SELECTION

After removal of duplicates and conference abstracts, citations were uploaded into DistillerSR (Evidence Partners, Ottawa, Canada). Using prespecified inclusion and exclusion criteria (Table 2), titles and abstracts were screened by 2 reviewers. Articles included by either reviewer underwent full-text review. At full-text review, 2 individuals decided on inclusion/exclusion by consensus (input from a third reviewer was requested as needed). A list of studies excluded at full-text review is provided in Appendix B.

Eligible populations were adults (≥ 18 years of age) living in US nursing homes. Studies were excluded if evaluating other types of congregant settings (eg, homes for those with developmental disabilities or transitional housing for addiction treatment). Eligible articles addressed the effects of nurse staffing levels (eg, nurse hours per patient) or skill mix (eg, ratio of RN to total nursing staff) on processes of care (eg, receipt of antipsychotics and receipt or duration of urinary catheter) and/or resident outcomes (eg, pressure ulcers, nursing home-associated infections, and pain).

Table 2 Inclusion and Exclusion Criteria

| Inclusion Criteria | Exclusion Criteria
Population | 18 years or older residents of nursing homes | < 18 years of age; living in group homes for mental health or developmental disabilities, or transitional housing for addiction recovery, etc
Intervention | Staffing levels and staff mix: RN, LPN, NA (eg, nurse hours per resident, nurse to resident ratios, RN to total nurse staffing ratios) | Non-nurse disciplines
Comparator | Any
Outcomes | - Process Outcomes; – Receipt of antipsychotic, antianxiety, or hypnotic medication; – Receipt and/or duration of urinary catheter; – Deficiency citations for resident safety or quality of care; - Resident Outcomes; – Nursing home-associated infections (eg, urinary tract infection, influenza, pneumonia, COVID-19); – Pressure ulcers (new or worsened); – Falls with major injury; – Acute care episodes (hospitalizations, emergency room visits); – Discharge to home or community; – Functioning (ability to move independently, increase in needing help with activities of daily living); – Pain severity; – Quality of life; – Mortality; - Cost Effectiveness; – Cost per outcome; Cost per quality-adjusted life year
Timing | Any
Setting | United States nursing homes (includes Community Living Centers and State Veterans Homes) | Assisted living facilities, facilities exclusively focused on acute care settings (ie, emergency rooms and inpatient floors) or congregant settings that are not providing skilled nursing services (ie prison, etc)
Study Design | Randomized controlled trials or observational studies | Reviews, study protocols, case studies, editorials, qualitative, no comparison group

## DATA ABSTRACTION AND QUALITY ASSESSMENT

Study quality was independently assessed by 2 reviewers using a modified version of the Joanna Briggs Institute Critical Appraisal Tool Checklist for Analytical Cross-Sectional Studies (Appendix C).^20^ The original tool included 8 domains: inclusion criteria, study subject and setting description, exposure measurement, identification of confounders, strategies to deal with confounders, outcome measurement, and statistical analysis. To make these criteria more applicable for longitudinal observational studies, we added 2 domains: whether the explanatory variable preceded assessment of outcomes of interest, and whether follow up was complete and adequately described. Generally, a study rated as having methodological concerns in 2 or more domains was considered low quality overall. If needed, a third reviewer also evaluated the study to help reach consensus on the quality rating. Ratings for eligible studies can be found in Appendix D.

Abstracted data from all eligible studies included the following: study design, setting and population characteristics, data sources, definitions of nurse staffing and/or skill mix, and processes of care or resident outcomes evaluated. For studies rated as moderate or high quality, we also abstracted detailed results on characteristics of staffing (amount and different types of nurse staffing, including total staffing [RN, LPN, and NA]); effects or associations between nurse staffing (or skill mix) and processes of care or resident outcomes; and detailed analytic methods (eg, consideration of confounders and analytic models). We categorized data sources into 5 large categories (Table 3). We also noted if study outcomes were attributed separately for VA vs non-VA facilities, or if the study primarily involved VA facilities. Data were abstracted by 1 person and over-read by second. If needed to resolve conflicts, a third reviewer also evaluated the study.

Table 3 Data Sources

Category | Data Sources
CMS | Minimum Data Set (MDS); Online Survey Certification and Reporting (OSCAR); Certification and Survey Provider Enhanced Reporting (CASPER); CMS National Health Safety Network Public File; Nursing Home Compare Archives (NHC); Payroll Based Journal; Provider of Service; Medicare & Medicaid claims data; Medicare Healthcare Cost Report Information System (HCRIS)
Other Federal | LTCFocus (https://ltcfocus.org/); National Nursing Home Survey (CDC); Census; Area Health Resource File
State Agencies | State Agency Data; California Cost Report
Infectious Disease | Hopkins COVID-19 Dashboard; National Outbreak Reporting System (NORS); COVID-19 Nursing Home Dataset
Other | Company or corporation data; News organizations; American Hospital Association Database; Surveys (independent study); Direct observation or time study

## SYNTHESIS & CERTAINTY OF EVIDENCE

Due to heterogeneity in populations, methods, and outcomes of included studies, we performed qualitative synthesis of the results. We summarized key study findings categorized by the processes of care and/or resident outcomes being evaluated. For the 3 high-priority outcomes (pressure ulcers, nursing home-associated infections, and pain), we also rated overall certainty of evidence using a GRADE approach.^21–23^ Briefly, for each outcome and nurse staffing variable, we evaluated characteristics of the evidence across 5 domains: methodological limitations, imprecision, inconsistency, indirectness, and publication bias. For methodological limitations, we considered factors such as accuracy of data assessment (for both outcomes and nurse staffing), timing of outcomes with respect to nurse staffing data, and use of appropriate analytical models. To evaluate indirectness, we examined how applicable the results were to our key questions, including population characteristics and type of outcomes assessed. For imprecision, we considered the number of events, sample size, and precision of effect estimates reported by included studies. Inconsistency relates to whether the direction and magnitude of effects are similar (or different) across the included studies. Finally, we considered the role of publication bias, which may lead to preferential reporting of positive results (particularly from small studies or those looking at many different outcomes). The overall certainty of evidence takes into consideration individual ratings in each of these 5 domains, but domains may not be weighted equally in determining the overall rating.