# INTRODUCTION

## PURPOSE

The VA Evidence Synthesis Program (ESP) was asked by the VA Office of Nursing Services, in collaboration with Geriatrics and Extended Care, for an evidence review on the effects of nurse staffing levels and skill mix on quality of care and resident outcomes in nursing homes. Findings from this review will be used to guide the development of nurse staffing recommendations for VA nursing homes, as well as to inform VA guidance for State Veterans Homes.

## BACKGROUND

In the United States (US), 1.3 million people reside in more than 15,000 nursing homes.^2,3^ Nursing homes are complex environments with heterogenous populations needing rehabilitative post-acute, end-of-life, or custodial long-term care. Nursing home residents have diverse care needs and diagnoses that vary within and across facilities.^4^ Nursing homes may be stand-alone facilities (independently owned or part of a network of facilities) or part of integrated care networks that include hospitals and clinics or continuing care communities that include independent and assisted living units.^5^ Within nursing homes, direct care nursing staff (ie, registered nurses [RN], licensed vocational or practical nurses [LPN], and nursing assistants [NA]) are the primary caregivers for residents^6^; thus, the level and characteristics of nursing staff are likely to impact resident well-being, health, safety, and quality of life.

US nursing homes are governed by complex regulatory and payment policies.^7^ States license nursing homes to operate, and the Centers for Medicare and Medicaid Services (CMS) certifies facilities to receive Medicare and/or Medicaid payments. Almost all US nursing homes are CMS certified. Although the Institute of Medicine recommends that nursing homes have at least 1 RN on duty 24 hours a day,^7,8^ federal and state regulations do not currently require this level of nurse staffing.^9^ Federal regulations only require having at least 1 RN on duty 8 hours a day, and that nursing homes have sufficient staff to provide nursing care to all residents (Nursing Home Reform Act 1987).^10^ States can impose more stringent regulations but none currently require that nursing homes have an RN on duty 24 hours per day. State regulations typically require a specific number of nursing hours per resident per day (HPRD). For example, California currently requires a minimum of 3.5 HPRD of direct nurse staffing.^11,12^ As part of the Nursing Home Compare 5-Star Rating System, CMS calculates expected staffing levels based on resident acuity; CMS estimates that the average US nursing home should have 4.2 hours of nursing HPRD.^6^ However, most nursing homes have staffing levels below this.^6,13^ There are also large daily variations in staffing levels within certain facilities, and some evidence that facilities may increase staffing to coincide with annual inspections.^13^

The Department of Veterans Affairs (VA) operates 134 nursing homes, called Community Living Centers (CLCs), that together currently provide a total of 8,480 beds.^1^ CLCs are often attached to VA medical centers or hospitals, but may also be stand-alone facilities.^14^ Due to VA nurse staffing requirements, CLCs have higher levels of nurse staffing than non-VA community nursing homes. CLCs serve a variety of resident populations, which may on average have higher acuity and complexity of needs than residents in most non-VA community nursing homes.^15^

There is also a set of State Veterans Homes that are independently run by state governments. These State Veterans Homes must meet federal and state regulations for nursing homes, but do not have to adhere to the same VA nurse staffing requirements as CLCs. VA has responsibility for certifying that State Veterans Homes meet certain standards and conducts annual surveys to make these determinations.

Although some studies have indicated that higher nurse staffing levels lead to better resident outcomes,^16–18^ it remains unclear how overall nurse staffing levels and skill mix can be optimized to achieve improvements in process of care (eg, limited use of antipsychotics) and resident outcomes (eg, decreased pressure ulcers and pain), particularly in the setting of constraints due to cost and nursing workforce availability.

We conducted a systematic review on the effects of nurse staffing levels and staff mix on processes of care and resident outcomes in nursing homes. In this report, we summarize the evidence on effects of nurse staffing levels and skill mix on a variety of outcomes, beginning with those selected as high priority: pressure ulcers, nursing home-associated infections, and pain outcomes. For these high-priority outcomes, we also provide certainty of evidence for the summary findings. We then describe results for additional outcomes, including urinary catheters, functioning, quality of life, and hospitalizations, among others. Finally, we discuss implications of these results for VA policy and recommendations for future research.