# ABBREVIATIONS TABLE

Abbreviation: Definition
ADL: Activities of daily living
CDC: Centers for Disease Control and Prevention
CI: Confidence interval
CLC: Community Living Center
COE: Certainty of Evidence
CMS: Centers for Medicare and Medicaid Services
ESP: Evidence Synthesis Program
HPRD: Hours per resident day
KQ: Key question
LPN: Licensed practice/vocational nurse
MDS: Minimum Data Set
MeSH: Medical subject heading
NA: Nursing assistant
NH: Nursing home
NHC: Nursing Home Compare
NORS: National Outbreak Reporting System
NR: Not reported
OR: Odds ratio
PAH: Potentially avoidable hospitalizations
RN: Registered nurse
TEP: Technical expert panel
US: United States
UTI: Urinary tract infection
VHA: Veterans Health Administration