# APPENDIX F EVIDENCE TABLES

Appendix Table F-1 Nursing Home Staffing Associations with Urinary Catheter Usage, Nursing Home-Associated Infections (non-COVID-19), and Pressure Ulcers

Appendix Table F-2 Nursing Home Staffing Associations with COVID-19

Appendix Table F-3 Nursing Home Staffing Associations with Resident Pain and Functioning Outcomes

Appendix Table F-4 Nursing Home Staffing Associations with Quality of Life

Appendix Table F-5 Nursing Home Staffing Associations with Hospitalizations

Appendix Table F-6 Nursing Home Staffing Associations Deficiency Citations

Appendix Table F-7 Nursing Home Staffing Associations with Receipt of Antipsychotics, Falls, Discharge to Community, and Mortality