# APPENDIX E PEER REVIEW DISPOSITION

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | Thank you.
2 | 3 | Yes | Thank you.
3 | 4 | Yes | Thank you.
4 | 5 | Yes | Thank you.
5 | 6 | Yes | Thank you.
6 | 9 | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence?
7 | 1 | No | Thank you.
8 | 3 | No | Thank you.
9 | 4 | No | Thank you.
10 | 5 | No | Thank you.
11 | 6 | No | Thank you.
12 | 9 | No | Thank you.
Are there any published or unpublished studies that we may have overlooked?
13 | 1 | No | NA
14 | 3 | Yes - See my general comments for additional papers that should be included, and why; Nurse staffing and patient outcomes: Strengths and limitations of the evidence to inform policy and practice. A review and discussion paper based on evidence reviewed for the National Institute for Health and Care Excellence Safe Staffing guideline development. P. Griffiths, J. Ball, J. Drennan, C. Dall’Ora, J. Jones, A. Maruotti, . Int J Nurs Stud 2016 Vol. 63 Pages 213–225 Accession Number: 27130150 DOI: 10.1016/j.ijnurstu.2016.03.012 27130150; Nurse staffing and inpatient hospital mortality. J. Needleman, P. Buerhaus, V. S. Pankratz, C. L. Leibson, S. R. Stevens and M. Harris. N Engl J Med 2011 Vol. 364 Issue 11 Pages 1037–45. Accession Number: 21410372 DOI: 10.1056/NEJMsa1001025 21410372; Winter SG, Bartel AP, de Cordova PB, Needleman J, Schmitt SK, Stone PW, Phibbs CS. The Effect of Data Aggregation on Estimations of Nurse Staffing and Patient Outcomes. In press, Health Services Research, 2021;56(6):1262–1270. DOI: 10.1111/1475-6773.13866 PMID: 3437818134378181 | Thank you for the suggested articles; however, none of these met our inclusion criteria. Griffiths et. al. is a review article, and not an eligible study design. Needleman et. al. and Winter et al. both addressed nurse staffing in hospitals, which was not an eligible setting for this review.
15 | 4 | Yes - Please see below re: COVID19 papers (comment 3c) and acknowledgment of other reviews that have been done on this literature (comment 4) | We note again that published reviews are not eligible for inclusion in this systematic review. We examined the studies included by the suggested review, and did not find any additional eligible articles for our review. Several of the articles included by the other review are already included in our review. One of the articles included by the suggested review, McGarry 2021, was published after our original search date. We now refer to this article in the Discussion, and note that these results would not have changed our overall findings or conclusions.
16 | 5 | No | NA
17 | 6 | No | NA
18 | 9 | No | NA
Additional suggestions or comments can be provided below.
19 | 1 | This is a systematic review of nurse staffing in nursing homes and associated outcomes using 4 databases with a structured literature search. Because nurse staffing is never randomized, the systematic review focuses on cohort studies of nurse staffing and patient outcomes including pressure ulcers (PU), nursing home infections (NHAI), hospitalizations, pain and catheters. Studies were evidence graded and have variable quality. The authors separate the staffing questions into RN, LPN and NA for each outcome. | NA
19 | 1 | The executive summary is fairly long (14 pages). I am not sure of the ESP standards but typically exec summaries are 1-2 pages. The detail will be appreciated by some reviewers, but not by others. | The Executive Summary in this report is consistent with length of summaries in other ESP reports. Generally, ESP Executive Summaries are more than 2 pages long. It is unclear if reviewer is perhaps thinking of ESP management ebriefs (which are shorter, targeted communications that are prepared after the final report), or perhaps another ESP product (eg, Evidence Briefs). However, per reviewer’s concern, we have further edited the executive summary for greater brevity.
19 | 1 | Page 8 Line 33-34 – please check the federal VA budget for currently operational CLC beds. The number is closer to 8500. | We originally referenced a government report that described VA CLC’s in 2018. Per reviewer’s suggestion, we have now updated the number of CLC beds based on VA’s proposed FY 2022 budget (8,480).
19 | 1 | Page 10 Line 34 Pressure Ulcers – Is there a GRADE for this evidence? How is age of the literature accounted? Most of these analyses were related to MDS 2.0 in a time when staffing was measured by self-report (not CMS payroll journal records). The preponderance of studies by 1 group is potentially a strength (the researchers know the topic and measurement structure) and a bias (“we are hell bent on showing that RN staffing is critical and LPN staffing is…”); Page 11, NHAI – is there a GRADE for the evidence? | In the main text, Table 5 provides the summary of results and GRADE ratings for pressure ulcers. Similarly, Table 6 describes the results and GRADE ratings for nursing home-associated infections. GRADE ratings take into account methodological limitations (including concerns regarding accuracy or bias of datasources) and overall consistency of results across studies, along with other domains (see Methods). The concern with age of the literature, if not directly related to accuracy of the data, would be considered in the Indirectness domain, which looks at whether study results are applicable and meaningful for the KQ addressed by our review.
19 | 1 | | For consistency, we have reported p-values throughout this review with the leading zero.
19 | 1 | Page 12, line 23 – Do you need an extra zero in the p-value?
19 | 1 | Page 12, line 18 – Was community prevalence and facility size included in these studies? Both increase the likelihood of introduction into NHs. | All 4 studies described in this section had controlled for nursing home size. Three of these also adjusted for a measure of COVID-19 prevalence in the community (eg, COVID-19 cases per 1,000 residents). We have added this information to the Results.
19 | 1 | Page 12, line 56 – I very much appreciate the analysis of UTI. While perhaps outside the scope, I am wondering if the studies postulated a potential mechanism. The reason for the comment is that this section may be intertwined with the Urinary Catheter analysis. | We appreciate reviewer’s suggestion regarding potential link between the use of urinary catheters and rates of UTI in nursing homes. However, this relationship was not examined in the 3 moderate-quality studies which addressed both UTI and urinary catheters (Trinkoff 2013, Lee 2014, and Castle 2010). Instead, urinary catheters and UTI (both assessed using MDS) were modeled as different outcomes in separate analyses. Additionally, there were several studies that examined only urinary catheters or UTI, without having the other outcome.
19 | 1 | In addition, it may be important to include dates on these studies (at least pre & post MDS 3.0), the differences in the MDS 2.0 and MDS 3.0 are important. Also there have been various initiatives over the years. | We note both the publication dates and the dates of data (for nurse staffing and outcomes) in Appendix tables. We agree that changes in outcomes assessment (eg, due to newer reporting processes to MDS) are important considerations and have highlighted these in the relevant Results sections and the Discussion.
19 | 1 | | Thank you.
19 | 1 | Page 14 Line 6 – Of the 6 studies, 5 were conducted by the same PI? Thanks for bringing it up – see comment about bias above.; Page 15 line 7 – Similar comment on bias by a single PI Should this be included with NHAI – UTI? Perhaps not, but the clinical undertone of catheter use is UTI predisposition…; Page 15 line 46 – Should there be a comment that sometimes the MDS was after the staffing measurement? | As noted above, there were several studies that addressed UTI but not urinary catheters. Only 1 of the 5 studies examining UTI were conducted by Castle et al.; The timing of staffing and outcomes assessment was a substantial methodological limitation for many of the included studies. We have provided more information about this for the specific section indicated by reviewer, and also expanded on this in the Results overview and Discussion.
19 | 1 | Page 16 line 42 – were all deficiency citations included? Some deficiencies are directly related to staffing. | We describe in greater detail the type of deficiency citations within the main text Results and in Appendix Table F-6. Eligible studies addressing deficiency citations counted a variety of different citations, but these had to be relevant to resident safety and/or quality of care (eg, infection control or medication management). We have clarified this in the Executive Summary—Results section.; We have ensured that all GRADE certainty of evidence ratings are included in the text of the Executive Summary in each applicable section.
19 | 1 | For the summary of Key findings Page 18 line 9 – please make sure that all of the GRADES are included in the text of the executive summary. | We have added this citation to the Discussion.
19 | 1 | Page 20 line 6 – there is finally a reference for the VA CLC Population: https://www.jamda.com/article/S1525-8610(21)00910-5/fulltext | Thank you.
19 | 1 | Page 20 line 19-24 – Great example and important point! Page 21 line 28 – Great point about changes in NHs since 2000.; Page 25 Fig 1 – I am not sure how AP meds are a ‘process’, but will allow for your conceptual diagram.; Page 34 table 5 – these are really powerful tables! I know that you have referenced the methodology. Please consider giving a paragraph or footnote to defining each of the column headers | The prescribing and use of a medication is usually considered a process in the Donabedian model. A process of care is defined as “what is actually done in giving and receiving care” [Donabedian, JAMA 1988].; Thank you. The GRADE methodology for determining certainty of evidence is complex and tailored to the specific outcomes of interest. We have provided citations and greater explanation in the relevant Methods section (main text).
20 | 3 | Overall, the review conducted is sound and the conclusions are supported by the evidence. | Thank you.
20 | 3 | One issue that should probably be noted is that the 1 VA CLC nurse staffing study included in this review used a statistical method that, given the very high VA staffing levels, was essentially set up to not find effects for staffing levels. That study was designed to look at the effects of unit tenure on outcomes; it did find that increased RN and LPN tenure was associated with better outcomes. Since it used a fixed-effects model, the estimates for the effect of staffing (HPPD) were driven by deviations from each unit’s average staffing level. Given the very high VA CLC staffing levels (see below), modest reductions in staffing probably can’t be expected to have any effect on patient outcomes. A note to this effect should probably be added to the detailed discussion of the findings of this paper. | We agree that comparisons among VA CLCs would only detect impacts of nurse staffing that are relevant at high staffing levels, particularly as compared with non-VA community nursing homes. However, we do not believe that this limitation could be addressed by different statistical techniques (eg, using random effects models). In the Discussion, we have emphasized that no eligible study compared outcomes between VA and non-VA nursing homes, and that this is a substantial gap in the evidence.
20 | 3 | In the discussion, I think that more emphasis/comment needs to be made to make it very clear that the staffing in CLCs is very different from community nursing homes. There are several relevant issues.; 1. VA RN wages are set by law to match of the average of the CMS wage index, and this is dominated by the nursing salaries for RNs working in acute care. Acute care RNs receive a premium, compared to RNs who work in other settings, thus the wages that VA pays for RNs working in CLCs are above market.; 2. Related, there is some evidence that at least some RNs take positions in the CLC as a stepping stone to get into the VA, and then transfer to another RN position when 1 becomes available.; 3. For LPNs and Aides, the VA wage differential with the community nursing homes varies by market, but it is almost always competitive, and in some markets may be above market.; 4. For all nursing staff, the VA benefit package is almost always better than the average benefit package for community nursing homes, sometimes significantly better.; 5. For LPNs and Aides, the VA offers training benefits that are, on average, significantly better than what is offered in the community; these are set to match those offered by acute care hospitals. Thus, there is a path to advance up the ladder with sudsidized training that is not offered by many community nursing homes.; 6. **** All of the above contribute to VA being considered to be a top-tier employer for staff working in nursing homes. This results is MUCH lower staff turnover. The average tenure of an Aide working on a specific CLC unit in the VA is over 4 years, while in most community nursing homes it is less than a year! | We have expanded the Discussion section describing the many differences between VA CLCs and community nursing homes. We agree with reviewer that VA work environment and salary/benefits are likely more attractive for many nurses, but we did not find published references or publicly available reports that clearly describe these differences. Thus, we discuss these potential differences in work environment and other workforce factors in more general terms.
20 | 3 | Related note, on page 20 it is noted that nursing homes may be a less desirable type of employment, compared to hospitals, due to differences in salary and benefits. While this is true in general, it does not apply to the VA, given how VA wages and benefits are set. | As noted above, we have highlighted differences between VA CLCs and community nursing homes. This sentence addressed the situation for community nursing homes, as most eligible studies used data for community facilities.
20 | 3 | Main comment is that the discussion of the findings and limitations of the existing evidence only considers the work that has been done looking at how nurse staffing affects patient outcomes for long term care. The number of high-quality studies is limited, and there are some lessons that could potentially be learned from the work that has been done for acute medical/surgical care.; Specifically, there is a very good summary of the limitations of the work on nurse staffing in acute care by Griffiths et al, 2016. Listed at end of this file. Many of the issues identified in that paper are also relevant to long term care. | The impact of nurse staffing on outcomes in acute care settings is outside the scope of this review. We agree that there are likely similar concerns regarding methodological limitations and gaps in evidence.
20 | 3 | Endogeneity and how nurse staffing is measured are key limitations of much of the literature on how nurse staffing affects patient outcomes. It was noted that many of the studies relied on surveys to determine nurse staffing levels, and this method is subject to bias. Further, with only a few exceptions, most of the studies of nurse staffing rely in very aggregated data to measure nurse staffing (e.g., annual data). This masks the fact that there can be considerable variation in staffing levels over time. Again, from the acute care literature, Winter et al, 2021 show that there is considerable aggregation bias. Further, Needleman et al, 2011 show that shift to shift variance in staffing affects outcomes. | We agree that method of assessing nurse staffing is a major methodological concern for this body of evidence (and an important reason that there is low certainty of evidence for most outcomes). We have added the specific issue that data on nurse staffing did not allow for examination of variation (over time) in staffing levels.
20 | 3 | Minor Comment: Page 20, middle, estimated RN salary and benefits. The estimated RN salary is FAR too low. HERC annually creates a dataset of the average VA wage costs for each type of employee. For the most recent year, the average RN costs (salary plus benefits) for an FTE was $131,643 from MCA data and $136,406 using FMS data. The data in the report should be updated.; All of the above should then be factored into the discussion about the needs for additional research.; Nurse staffing and patient outcomes: Strengths and limitations of the evidence to inform policy and practice. A review and discussion paper based on evidence reviewed for the National Institute for Health and Care Excellence Safe Staffing guideline development. P. Griffiths, J. Ball, J. Drennan, C. Dall’Ora, J. Jones, A. Maruotti, . Int J Nurs Stud 2016 Vol. 63 Pages 213–225 Accession Number: 27130150 DOI: 10.1016/j.ijnurstu.2016.03.012 27130150; Nurse staffing and inpatient hospital mortality. J. Needleman, P. Buerhaus, V. S. Pankratz, C. L. Leibson, S. R. Stevens and M. Harris. N Engl J Med 2011 Vol. 364 Issue 11 Pages 1037–45. Accession Number: 21410372 DOI: 10.1056/NEJMsa1001025 21410372; Winter SG, Bartel AP, de Cordova PB, Needleman J, Schmitt SK, Stone PW, Phibbs CS. The Effect of Data Aggregation on Estimations of Nurse Staffing and Patient Outcomes. In press, Health Services Research, 2021;56(6):1262–1270. DOI: 10.1111/1475-6773.13866 PMID: 3437818134378181 | We used an estimate for RN salary from publicly available information on salary.com; this most likely reflects community salaries. This is appropriate since most eligible studies examined outcomes in community nursing homes (and not VA CLCs). Additionally, we do not believe that these costs for VA nurses are publicly available (eg, these data are accessed via VA intranet sites). Thus, we have added a sentence that states generally that VA salaries tend to be higher. Finally, we used this example to highlight the high costs of changing nurse staffing to improve resident outcomes. Using the higher estimates for VA RN salaries would make this even more true (and not less so).; As noted above, evidence on impact of nurse staffing on outcomes in acute care facilities is outside the scope of this review.
21 | 4 | Thank you for the opportunity to review this synthesis of the literature assessing relationships between nursing home staffing and resident outcomes. Overall the review is well-organized, written clearly, and appears to have been conducted using robust methods. However, there are a number of issues that do need to be addressed. Please see below for specific comments. | Thank you.
21 | 4 | 1 There appears to be some miscoding of the quality assessments. In Appendix C, 1 would think that a ‘yes’ to all questions would equate with ‘high’ quality, but the note at the bottom suggests the opposite. I also see some discrepancies across tables – e.g. the Konetzka 2008 paper [ref 18] is given a rating of ‘low’ in Appendix D (even though it is regarded by most experts as 1 of the strongest papers in this literature); but then is later described as high quality in Appendix F-1. The Harrington 2020 paper [ref 10] is given a ‘low’ rating in Appendix D, but a ‘high’ rating in Appendix F-2. These are just 2 examples, but there appear to be other discrepancies. | These discrepancies were due to some inconsistencies in our terminology, namely that a study with high risk of bias is low overall quality and vice versa. We have corrected the appendix tables to consistently refer to “high” (or “low”) quality as appropriate.
21 | 4 | 2 There are several papers in Appendix D that do not appear in the Appendix F evidence tables, so were they actually included in the review of any outcomes? Among just the first few papers listed in Appendix D, I do not see Alexander, Bosco, or Bostick included anywhere in Appendix F. | As stated in the Methods, we did not undertake detailed data abstraction from low-quality studies; thus these are not included in detailed results tables (Appendix F).
21 | 4 | 3 The review of COVID-19 outcomes (p.11-12) needs to be expanded in three ways:; a. First, there needs to be some separation of outcomes – I would examine probability of any outbreak, case rates, and mortality rates separately, as these are conceptually different from 1 another. (i.e. Better staffing is unlikely to prevent the virus from initially walking in the door, but may help to mitigate outbreaks and adverse outcomes once an incident case is identified.); b. Quality assessment for COVID19 studies needs to include whether the study controlled for community virus prevalence & bed size, as these have been identified as the strongest and most consistent predictors of nursing home cases & deaths. See this review: https://pubmed.ncbi.nlm.nih.gov/34549415/; c. There are several other studies that have examined various aspects of NH staffing and COVID19 outcomes, most of which I believe were done within the timeframe of your review. See link in (3b), section on staffing, for some additional articles you probably should incorporate. | We present summary findings by different types of nurse staffing (eg, RN or LPN) because our Technical Expert Panel recommended this as the most useful and relevant format. Detailed results for each of these studies are described in Appendix Table F-2. We agree that there is substantial heterogeneity in outcomes assessed by studies examining COVID-19. For example, there were not only differences in terms of counting cases, outbreaks (variably defined), and/or deaths, but also in the method for data collection (eg, CMS data vs. newspaper reports). Additionally, 2 studies were focused on data within a single state, 1 study used national data, and 1 study examined only nursing homes participating in a COVID-19 vaccination program. Therefore, there are substantial conceptual differences and concerns on multiple levels (beyond the type of outcomes included) in aggregating results across these studies. These concerns led to the “Low” and “Very Low” GRADE ratings for summary findings regarding COVID-19. Additionally, as part of quality assessment and determining the GRADE ratings, we also considered whether studies controlled for community prevalence and nursing home size. We have provided more information on these analytic factors in the Results. Please see above response to comment #15 (Reviewer 4) regarding articles included by Konetzka et al. review.
21 | 4 | 4 There have been at least 6 reviews of the nursing home staffing-quality literature to date (listed below), and an additional review of nursing home hospitalizations that included a section on staffing (Grabowski et al, 2008). These should be mentioned somewhere in the discussion, with a comment as to how the current review adds to this existing evidence base, and how findings align or contrast with those of prior reviews. I see the Dellefield review in your reference list but couldn’t find an in-text citation. I don’t believe any of these others were cited.; a. Bostick JE, Rantz MJ, Flesner MK, Riggs CJ. Systematic review of studies of staffing and quality in nursing homes. J Am Med Dir Assoc. 2006;7(6):366–376.16843237; b. Castle NG. Nursing home caregiver staffing levels and quality of care - A literature review. Journal of Applied Gerontology. 2008;27(4):375–405.; c. Dellefield ME, Castle NG, McGilton KS, Spilsbury K. The Relationship Between Registered Nurses and Nursing Home Quality: An Integrative Review (2008-2014). Nursing Economics. 2015;33(2):95-+.26281280; d. Spilsbury K, Hewitt C, Stirk L, Bowman C. The relationship between nurse staffing and quality of care in nursing homes: a systematic review. Int J Nurs Stud. 2011;48(6):732–750.21397229; e. Backhaus R, Verbeek H, van Rossum E, Capezuti E, Hamers JP. Nurse staffing impact on quality of care in nursing homes: a systematic review of longitudinal studies. J Am Med Dir Assoc. 2014;15(6):383–393.24529872; f. Clemens S, Wodchis W, McGilton K, McGrail K, McMahon M. The relationship between quality and staffing in long-term care: A systematic review of the literature 2008-2020. Int J Nurs Stud. 2021;122:104036.34419730; g. Grabowski DC, Stewart KA, Broderick SM, Coots LA. Predictors of nursing home hospitalization: a review of the literature. Med Care Res Rev. 2008;65(1):3–39.18184869 | This ESP report was conducted primarily to meet needs identified by our VA operational partners in the Office of Nursing Services, and Geriatrics and Extended Care. In our initial discussions with our VA partners, we noted there were previously published reviews, although most of these were conducted >5 years ago (the exception being the Clemens et al. review, which was not yet published at that time). For various reasons, the existing reviews did not meet the needs of our partners. As per recommended format for ESP reports, our Discussion focuses on interpretation of the evidence, including implications for VA policy and practice, and identification of evidence gaps. As systematic reviews were not eligible study designs for this report, we did not carefully assess and compare findings from reviews (such as those noted here). Therefore, we do not present detailed results or summaries from these reviews. We have added a more general comparison of our review with some of the previous systematic reviews. The Dellefield et al. review was cited already in the Introduction (page 25). Finally, some of these are not systematic reviews (eg, Castle 2008; Grabowski 2008) or largely included studies published >20 years ago (Bostick 2006).
21 | 4 | 5 Missing from the discussion is an acknowledgment that 1 of the biggest limitations of the staffing literature to date has been the predominance of studies using OSCAR/CASPER data, which was long criticized for reporting bias since it only captured facility-reported staffing levels around the time of survey. See discussion in the Castle 2008 review (https://journals.sagepub.com/doi/10.1177/0733464808321596) about this, and Exhibit 3 in Geng et al 2019 (ref 12) for an illustration of the reporting bias. This is why CMS transitioned to the current Payroll-based Journal system in 2016. | We agree with reviewer that there are substantial concerns with data accuracy nurse staffing. We have clarified and highlighted these concerns in the Discussion.
21 | 4 | 6 Discussion, p. 50, lines 28-31. The limitation about not measuring other organizational factors needs to be expanded, particularly as it relates to other workforce factors that impact resident outcomes. Staffing levels alone are very limited measures that solely tell us on average how many people are in the building, but tell us nothing about staff retention, turnover, agency use, consistency of assignments, staff engagement, or leadership. Evidence from hospitals suggests that higher nurse staffing is only associated with better patient outcomes in hospitals where other aspects of supportive work environments are also present (e.g. https://pubmed.ncbi.nlm.nih.gov/21945978/). There is only preliminary evidence on the contribution of work environment, measured from staff surveys, to resident outcomes in nursing homes (eg. refs 22, 28, 30, 57). There have been several papers on the negative consequences of turnover in nursing homes (by Castle and others) and CMS has just announced that they will begin reporting turnover measures in NH Compare which will allow for further exploration. I would acknowledge the need to develop these areas of evidence in your section on research gaps. | As suggested by the reviewer, we have expanded this Discussion paragraph to include a reference to new CMS data collection on turnover, and the likely importance of other workforce and work environment factors. Although some of the included studies did address factors such as turnover and use of agency staff, these were not the focus of this review. Therefore, we cannot state how important these specific factors may be, particularly as compared with nurse staffing levels, or whether there are substantial evidence gaps in understanding the role of these factors.
21 | 4 | Minor
21 | 4 | 7 Suggest adding number in-text citations throughout your results, at least when you are calling out specific studies. As is, it is difficult to tell which papers you are referencing as you summarize findings. | In-text citations are included throughout the Results section of the main text. Citations are not included in the Executive Summary as this is meant to be a more concise summary of the available evidence.
21 | 4 | 8 Pg. 19, line 47 – replace ‘physician extenders’ with the more appropriate term ‘advanced practice clinicians’ or ‘advanced practice providers’ | We have replaced this term with “non-physician providers”, as it is unclear whether advanced practice clinicians would include physician assistants (and other categories of non-physician providers).
22 | 5 | Page 9, line 3 - should be “function” (not “functioning”) --- also noted in other areas of the manuscript | Both “function” and “functioning” have been used in the. literature to describe ability to do (or difficulty with) daily tasks and participation in meaningful activities. For example, the Veterans SF-36 has a “physical functioning domain” [Kazis et al. Arch Intern Med, 1998] and ADLs have been used to assess “physical functioning” [Katz, JAMA, 1963].
22 | 5 | Page 11, line 24 - what is the definition of “total staffing”? Number of RN, LPN, and NAs combined? | We have added the definition of total staffing to Methods.
22 | 5 | Page 14, line 44-45 - missing “the” in “…nursing home being in THE highest 75th percentile for…” | This has been corrected.
22 | 5 | Page 15, line 28 - I believe this should be “Function” (not “Functioning”)… same comment for line 30 | See response above.
22 | 5 | Page 18, line 12, Discussion - this is the first time that the KQ 1 and 2 are mentioned in the Executive Summary section. Consider introducing KQ1 and 2 earlier in the Executive Summary. | We have added the KQ to the Methods in the Executive Summary.
22 | 5 | Page 19, line 46 (also on page 48, line 44) - in lieu of “physician extenders”, consider using actual roles (ie, nurse practitioners, physician assistants) - see https://www.aanp.org/advocacy/advocacy-resource/position-statements/use-of-terms-such-as-mid-level-provider-and-physician-extender | This has been addressed (see response to Reviewer #4 above).
22 | 5 | Page 20 line 40-41 - unclear sentence, please clarify - “.…VA CLCs to invest in additional avenues to improve specific resident outcomes have options.” | This sentence has been edited for clarity.
22 | 5 | Page 25, Figure 1 - shouldn’t there be a line from the “structure” directly to the “outcomes” as well (not just from “resident characteristics” to “outcomes”)? | The relationships between structure, processes, and outcomes are per previous descriptions of the Donabedian model (eg, Donabedian, JAMA 1988). In this figure, we only highlighted the processes of interest (for this review); there are clearly many other processes of care that would mediate the impact of organizational structure on resident outcomes. We have added ellipses to denote this.
22 | 5 | Page 26, Table 1 - RN Responsibilities column - RNs are also responsible for the application of the nursing process for each patient they care for, which includes identifying nursing diagnoses and implementation of nursing interventions that is individualized to the patient. | We used information from the Bureau of Labor Statistics for these general descriptions of different nurse staffing for nursing homes. We agree that there is variation in nursing practice across states, but also likely by settings (including different nursing homes).
22 | 5 | Another potential discussion point/limitation - nursing practice is governed by state nursing practice acts, which may affect processes of care and/or outcomes.
23 | 9 | Page 19 line 47 and page 48 line 44, the term physician extenders should not be used. If referring to advance practice providers (PAs, NPs, CNSs), either use the individual clinical professions, providers or the term advance practice providers. | This has been addressed (see response above to Reviewer #4).
23 | 9 | Page 49 and page 20, the sentence that starts on line 37 is not clear. | We have edited this sentence for clarity.