# APPENDIX D QUALITY RATINGS FOR ALL ELIGIBLE STUDIES

Author | Is it clear in the study that the “staffing level/ mix” preceded the outcome of interest? | Were the criteria for inclusion in the sample clearly defined? | Were the study subjects (ie, nursing homes) and the setting (ie, geography, national vs state, number of homes) described in detail? | Was the exposure (staffing level/mix) measured in a valid and reliable way? | Were confounding factors identified? | Were strategies to deal with confounding factors stated? | Were the outcomes measured in a valid and reliable way? | Was follow up complete and if not, were differences between groups in terms of their follow up adequately described and analyzed? | Was the appropriate statistical analysis used? | Overall
Abrahamson^54^ | Unclear | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | Moderate
Alexander^25^ | Unclear | Yes | Yes | Yes | No | No | Yes | Not applicable | Yes | Low
Arling^51^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | High
Bosco^37^ | Unclear | Yes | Yes | Yes | Unclear | No | Yes | Not applicable | Yes | Low
Bostick^34^ | Unclear | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | Low
Bowblis^60^ | Unclear | Yes | Yes | Yes | Yes | Yes | Yes | Unclear | Yes | Moderate
Castle^55^ | Unclear | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | Moderate
Castle^31^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | No | Yes | Moderate
Castle^33^ | Unclear | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | Moderate
Castle^36^ | Unclear | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | Moderate
Castle^26^ | Unclear | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | Moderate
Castle^56^ | Unclear | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Moderate
Castle^35^ | Unclear | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | Moderate
Castle^57^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | High
Castle^38^ | Unclear | Yes | Yes | Yes | Yes | Yes | No | Unclear | No | Low
Crawford^77^ | Yes | Unclear | Unclear | Yes | Yes | No | Yes | Yes | No | Low
Domi^48^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | High
Flynn^32^ | Unclear | Yes | Yes | Yes | Unclear | Unclear | Yes | Not applicable | Unclear | Moderate
Gorges^49^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | High
Harrington^11^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | High
Hefele^61^ | Unclear | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Moderate
Konetzka^18^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | High
Lee^28^ | Unclear | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | Moderate
Leland^62^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | High
Lerner^58^ | Unclear | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | Moderate
Li^39^ | Unclear | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | Moderate
Lin^27^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Unclear | Yes | Moderate
Ogunneye^45^ | No | Yes | Unclear | Unclear | Yes | No | Yes | Unclear | No | Low
O’Malley^46^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | High
Orth^42^ | Unclear | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | No | Moderate
Shin^53^ | Unclear | No | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | Moderate
Shin^78^ | Unclear | Yes | Yes | Yes | Yes | Yes | Unclear | Not applicable | Unclear | Low
Shippee^52^ | Unclear | Yes | Yes | Yes | Yes | Yes | Yes | Unclear | Yes | Moderate
Temkin-Greener^59^ | Unclear | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | Moderate
Temkin-Greener^30^ | Unclear | Yes | Yes | Yes | Yes | Yes | Unclear | Not applicable | Yes | Moderate
Thomas^43^ | Unclear | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | Moderate
Tong^64^ | Yes | Unclear | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | Moderate
Trinkoff^29^ | Unclear | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | Moderate
Trivedi^41^ | Unclear | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Moderate
Uchida-Nakakoji^40^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | High
Warren^63^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | High
White^24^ | Unclear | Unclear | Yes | Unclear | Yes | No | Yes | Unclear | No | Low
Xing^44^ | Unclear | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | Moderate
Xu^47^ | Unclear | Yes | Yes | Yes | Yes | Yes | Yes | Not applicable | Yes | Moderate