# APPENDIX C CRITERIA USED IN QUALITY ASSESSMENT

Question | Yes | No | Unclear
1. Is it clear in the study that the “staffing level/mix” preceded the outcome of interest?
2. Were the criteria for inclusion in the sample clearly defined?
3. Were the study subjects (ie, nursing homes) and the setting (ie, geography, national vs state, number of homes) described in detail?
4. Was the exposure (staffing level/mix) measured in a valid and reliable way?
5. Were confounding factors identified?
6. Were strategies to deal with confounding factors stated?
7. Were the outcomes measured in a valid and reliable way?
8. Was follow up complete and if not, were differences between groups in terms of their follow up adequately described and analyzed?
9. Was the appropriate statistical analysis used?

** If all responses are “yes” overall ROB = low, if 2 or more responses are “no” overall ROB = high, all other combinations overall ROB = moderate