# APPENDIX B EXCLUDED STUDIES

1 Nurse staffing hours is 1 of several factors that affect quality of care for nursing home residents. AHRQ Research Activities. 2000(243):13–13. Ineligible study design.
2 Staffing level mix affects quality of care in nursing homes. AHRQ Research Activities. 2009(343):6–7. Ineligible publication type.
3 Nursing homes using more agency staff have lower quality of care. AHRQ Research Activities. 2010(358):8–8. Ineligible publication type.
4 Staff shortages linked to infection citations in LTC. Hospital Infection Control & Prevention. 2011;38(6):68–70. Ineligible study design.
5 Nurse-patient ratios in aged care. Australian nursing journal (July 1993). 2013;20(7):4. Ineligible publication type.
6 LPN Supervision In Long Term Care Facilities. Iowa Board of Nursing Newsletter. 2014;33(3):8–8. Ineligible intervention.
7 Medication Incidents Occurring in Long-Term Care. Info Nursing. 2014;45(3):33–35. Ineligible setting.
8 RESIDENTIAL AGED CARE SERVICES and the employment of nursing staff. Nurses’ Paycheck. 2015;15(1):32–34. Ineligible publication type.
9 Akinci F, Krolikowski D. Nurse staffing levels and quality of care in Northeastern Pennsylvania nursing homes. Applied Nursing Research. 2005;18(3):130–137. No eligble outcomes.16106330
10 Algoso M, Ramjan L, East L, Peters K. An exploration of undergraduate nursing assistant employment in aged care and its value to undergraduate nursing education. Nurse education today. 2019;82:32–36. Ineligible setting.31422175
11 Álvarez Barbosa F, Pozo-Cruz B, Pozo-Cruz J, Alfonso-Rosa RM, Sañudo Corrales B, Rogers ME. Factors Associated with the Risk of Falls of Nursing Home Residents Aged 80 or Older. Rehabilitation Nursing. 2016;41(1):16–25. Ineligible setting.26399374
12 Alvarez MR, Kerr BJ, Burtner J, Ledlow G, Fulton LV. Effects of outsourced nursing on quality outcomes in long-term acute-care hospitals. Journal of Nursing Administration. 2011;41(3):138–143. Ineligible intervention.21336042
13 Alvarez MR, Kerr BJ, Burtner J, Ledlow G, Fulton LV. Use of outsourced nurses in long-term acute care hospitals: Outcomes and leadership preferences. Journal of Nursing Administration. 2011;41(2):90–96. Ineligible setting.21266888
14 Amuah J, Maxwell C, Cepoiu-Martin M, . Resident and facility predictors of hospitalization among older adults with dementia residing in assisted living facilities. Alzheimer’s and Dementia. 2012;8(4 SUPPL. 1):P429. Ineligible study design.
15 Antonova E, Zimmerman D. Scope and severity index: A metric for quantifying nursing home survey deficiency number, scope, and severity adjusted for the state-related measurement Bias. Journal of the American Medical Directors Association. 2012;13(2):e7–188. No eligble outcomes.21764389
16 Arling G, Abrahamson KA, Cooke V, Lewis T, Kane RL. Facility and market factors affecting transitions from nursing home to community. Medical Care. 2011;49(9):790–796. No eligble outcomes.21577163
17 Arling G, Mueller C. Nurse staffing and quality: The unanswered question. Journal of the American Medical Directors Association. 2014;15(6):376–378. Ineligible publication type.24703925
18 Armstrong-Evans M, Moss LA, Craven S, . Risk factors for resistance to antimicrobial agents among nursing home residents. American Journal of Epidemiology. 2003;157(1):40–47. Ineligible population.12505889
19 Arnetz JE, Zhdanova LS, Elsouhag D, Lichtenberg P, Luborsky MR, Arnetz BB. Organizational climate determinants of resident safety culture in nursing homes. The Gerontologist. 2011;51(6):739–749. Ineligible intervention.21708985
20 Arshad MM, Asmar HA, Rahbar MH, . Risk factors for Salmonella Oranienburg outbreak in a nursing home in Michigan. Journal of the American Geriatrics Society. 2006;54(4):715–717. Ineligible study design.
21 Arts EEA, Landewe-Cleuren SANT, Schaper NC, Vrijhoef HJM. The cost-effectiveness of substituting physicians with diabetes nurse specialists: a randomized controlled trial with 2-year follow-up. Journal of advanced nursing. 2012;68(6):1224–1234. Ineligible setting.22004474
22 Askerud A, Conder J. Nurses’ role in long-term conditions care. Kai Tiaki Nursing New Zealand. 2016;22(10):16–17. Ineligible population.
23 Backhaus R, Beerens HC, Verbeek H, Hamers JPH, van Rossum E. Rethinking the Staff-Quality Relationship in Nursing Homes. Journal of Nutrition, Health and Aging. 2018;22(6):634–638. Ineligible study design.
24 Baltiter T, Hilou M. Home nursing-home administration of oral chemotherapy. International Journal of Gynecological Cancer. 2012;22(SUPPL. 3):E971–E972. Ineligible publication type.
25 Barker KN, Flynn EA, Pepper GA, Bates DW, Mikeal RL. Medication errors observed in 36 health care facilities. Archives of internal medicine. 2002;162(16):1897–1903. Ineligible intervention.12196090
26 Barry T, Brannon D, Mor V. Nurse aide empowerment strategies and staff stability: Effects on nursing home resident outcomes. Gerontologist. 2005;45(3):309–317. No data 2000 or later.15933271
27 Bates-Jensen BM, Schnelle JF, Alessi CA, Al-Samarrai NR, Levy-Storms L. The effects of staffing on in-bed times of nursing home residents. Journal of the American Geriatrics Society. 2004;52(6):931–938. No eligble outcomes.15161457
28 Berlowitz DR, Rosen AK, Wang F, . Purchasing or providing nursing home care: can quality of care data provide guidance. Journal of the American Geriatrics Society. 2005;53(4):603–608. No data 2000 or later.15817005
29 Bernard B, Unroe KT, Callahan CM, Stump TE, Tu W. Variation in Hospice Services by Location of Care: Nursing Home Versus Assisted Living Facility Versus Home. Journal of the American Geriatrics Society. 2017;65(7):1490–1496. Ineligible intervention.28295145
30 Bertrand RM, Porchak TL, Moore TJ, . The nursing home dining assistant program: a demonstration project. Journal of gerontological nursing. 2011;37(2):34–43. Ineligible intervention.
31 Bjarnadottir RI, Herzig CTA, Travers JL, Castle NG, Stone PW. Implementation of Electronic Health Records in US Nursing Homes. CIN: Computers, Informatics, Nursing. 2017;35(8):417–424. No eligble outcomes.
32 Blewett LA, Johnson K, McCarthy T, Lackner T, Brandt B. Improving geriatric transitional care through inter-professional care teams. Journal of Evaluation in Clinical Practice. 2010;16(1):57–63. Ineligible intervention.19659690
33 Bliss DZ, Zehrer C, Savik K, Smith G, Hedblom E. An economic evaluation of four skin damage prevention regimens in nursing home residents with incontinence: economics of skin damage prevention…including commentary by Fader M. Journal of Wound, Ostomy & Continence Nursing. 2007;34(2):143–152. Ineligible intervention.
34 Bonner A, Rapp MP, Buri JB, Aigner MJ, Drew S, Phipps J. Nurse practitioner/physician collaborative models of care…Aigner MJ, Drew S, Phipps J. A comparative study of nursing home resident outcomes between care provided by nurse practitioners/physicians versus physicians only. JAMDA 2004;5:16-23. Journal of the American Medical Directors Association. 2004;5(3):219–221. Ineligible study design.15160733
35 Bowblis JR. Staffing ratios and quality: An analysis of minimum direct care staffing requirements for nursing homes. Health Services Research. 2011;46(5):1495–1516. Ineligible intervention.21609329
36 Bowblis JR, Applebaum R. How Does Medicaid Reimbursement Impact Nursing Home Quality? The Effects of Small Anticipatory Changes. Health Services Research. 2017;52(5):1729–1748. Ineligible intervention.27581748
37 Bowblis JR, Meng H, Hyer K. The urban-rural disparity in nursing home quality indicators: The case of facility-acquired contractures. Health Services Research. 2013;48(1):47–69. No eligble outcomes.22670847
38 Boyd M, Armstrong D, Parker J, . Do gerontology nurse specialists make a difference in hospitalization of long-term care residents? Results of a randomized comparison trial. Journal of the American Geriatrics Society. 2014;62(10):1962–1967. Ineligible intervention.25283552
39 Brady L. Prompted voiding yields results. CNAs are key to the success of a pilot study that reduced urinary incontinence for residents of 1 Illinois facility. Provider (Washington, DC). 2009;35(3):41–44. Ineligible intervention.
40 Brady L. Focus on caregiving. Prompted voiding yields results: CNAs are key to the success of a pilot study that reduced urinary incontinence for residents of 1 Illinois nursing facility. Provider. 2009;35(3):41–44. Ineligible intervention.
41 Braun RT, Yun H, Casalino LP, . Comparative Performance of Private Equity-Owned US Nursing Homes during the COVID-19 Pandemic. JAMA Network Open. 2020;3(10):e2026702. Ineligible intervention.33112402
42 Brookhart MA, Stedman M, Avorn J, Mogun H, Solomon DH, Parikh S. Correlations of nursing home characteristics with prescription of osteoporosis medications. Bone. 2011;48(5):1164–1168. Ineligible intervention.21320653
43 Brown KA, Daneman N, Jones M, . The Drivers of Acute and Long-term Care Clostridium difficile Infection Rates: A Retrospective Multilevel Cohort Study of 251 Facilities. Clinical Infectious Diseases. 2017;65(8):1282–1288. Ineligible intervention.28595289
44 Brownlee MA. The solution to the staffing crisis in LTC may be with the millennial generation [full title below]. Annals of Long-Term Care. 2010;18(3):19–20. No eligble outcomes.
45 Brühl A, Planer K, Hagel A. Variation of Care Time Between Nursing Units in Classification-Based Nurse-to-Resident Ratios: A Multilevel Analysis. Inquiry (00469580). 2018;55:1–9. Ineligible setting.
46 Buljac-Samardzic M, Van Woerkom M. Improving quality and safety of care in nursing homes by team support for strengths use: A survey study. PLoS ONE. 2018;13(7):e020006. Ineligible setting.
47 Burgermaster M, Slattery E, Islam N, Ippolito PR, Seres DS. Regional Comparison of Enteral Nutrition–Related Admission Policies in Skilled Nursing Facilities. Nutrition in Clinical Practice. 2016;31(3):342–348. No eligble outcomes.26993318
48 Bushnell PT, Bailer AJ, Collins JW, Stayner LT, Park RM. Impact of publicly sponsored interventions on musculoskeletal injury claims in nursing homes. American Journal of Industrial Medicine. 2009;52(9):683–697. No eligble outcomes.19670260
49 Cai S, Rahman M, Intrator O. Obesity and pressure ulcers among nursing home residents. Medical Care. 2013;51(6):478–486. Ineligible intervention.23666490
50 Canavan ME, Sipsma HL, Bradley EH, Aldridge Carlson MD. Hospice for nursing home residents: Does ownership type matter? Journal of Palliative Medicine. 2013;16(10):1221–1226. No eligble outcomes.23895303
51 Carter MW. Factors associated with ambulatory care - - sensitive hospitalizations among nursing home residents. Journal of Aging & Health. 2003;15(2):295–331. No data 2000 or later.12795274
52 Carter MW, Porell FW. Variations in hospitalization rates among nursing home residents: The role of facility and market attributes. Gerontologist. 2003;43(2):175–191. No data 2000 or later.12677075
53 Carter MW, Porell FW. Vulnerable populations at risk of potentially avoidable hospitalizations: the case of nursing home residents with Alzheimer’s disease. American journal of Alzheimer’s disease and other dementias. 2005;20(6):349–358. No data 2000 or later.
54 Carter MW, Porell FW. Nursing home performance on select publicly reported quality indicators and resident risk of hospitalization: grappling with policy implications. Journal of Aging & Social Policy. 2006;18(1):17–39. No data 2000 or later.16635979
55 Cassie KM, Cassie WE. Organizational and Individual Conditions Associated With Depressive Symptoms Among Nursing Home Residents Over Time. Gerontologist. 2012;52(6):812–821. Ineligible intervention.22547084
56 Castle N. Consistent staff assignment in Alzheimer’s special care units. Alzheimer’s and Dementia. 2011;7(4 SUPPL. 1):S292. Ineligible study design.
57 Castle N, Hanlon J, Handler S. Increasing antidepressant use in older nursing home patients. Pharmacoepidemiology and Drug Safety (PDS). 2009;18(S1):S92. Ineligible study design.
58 Castle NG. Nursing homes with persistent deficiency citations for physical restraint use. Medical care. 2002;40(10):868–878. No data 2000 or later.12395021
59 Castle NG. Nurse Aides’ ratings of the resident safety culture in nursing homes. International Journal for Quality in Health Care. 2006;18(5):370–376. Ineligible intervention.16959798
60 Castle NG. Use of agency staff in nursing homes. Research in gerontological nursing. 2009;2(3):192–201. Ineligible intervention.20078009
61 Castle NG. Staff assist: a resource to improve nursing home quality and staffing. The Gerontologist. 2011;51(5):714–722. Ineligible intervention.21610179
62 Castle NG. Consistent Assignment of Nurse Aides: Association With Turnover and Absenteeism. Journal of Aging and Social Policy. 2013;25(1):48–64. Ineligible intervention.23256558
63 Castle NG, Aiju M, Engberg J. Nurse aide agency staffing and quality of care in nursing homes. Medical Care Research and Review. 2008;65(2):232–252. Ineligible intervention.18227238
64 Castle NG, Castle NG. Differences in nursing homes with increasing and decreasing use of physical restraints. Medical Care. 2000;38(12):1154–1163. No data 2000 or later.11186294
65 Castle NG, Engberg J, Men A. Nursing home staff turnover: impact on nursing home compare quality measures. The Gerontologist. 2007;47(5):650–661. No eligble outcomes.17989407
66 Castle NG, Engberg JB. The influence of agency staffing on quality of care in nursing homes. Journal of aging & social policy. 2008;20(4):437–457. Ineligible intervention.19042556
67 Castle NG, Hyer K, Harris JA, Engberg J. Nurse Aide Retention in Nursing Homes. The Gerontologist. 2020;60(5):885–895. Ineligible intervention.32144426
68 Cen X, Li Y, Temkin-Greener H. Nursing Home Staff Turnover and Perceived Patient Safety Culture: Results from a National Survey. The Gerontologist. 2020;60(7):1303–1311. No eligble outcomes.32211874
69 Chen B-A, Lai F-C, Tsao L-I, Chien H-H, Chen C-F, Jeng C. Decision difficulties of long-term-care facility nurses in transferring residents to the emergency department: A cross-sectional nationwide study. Journal of advanced nursing. 2021. Ineligible setting.
70 Chen CK, Sloane PD, Eckert JK, . How good is assisted living? Findings and implications from an outcomes study. Journals of Gerontology - Series B Psychological Sciences and Social Sciences. 2005;60(4):S195–S204. No data 2000 or later.15980295
71 Chen MM, Grabowski DC. Intended and unintended consequences of minimum staffing standards for nursing homes. Health Economics (United Kingdom). 2015;24(7):822–839. Ineligible intervention.
72 Chisholm L, Weech-Maldonado R, Laberge A, Lin F-C, Hyer K. Nursing home quality and financial performance: Does the racial composition of residents matter? Health Services Research. 2013;48(6 PART1):2060–2080. No eligble outcomes.23800123
73 Corazzini KN, Anderson RA, Mueller C, Thorpe JM, McConnell ES. Licensed practical nurse scope of practice and quality of nursing home care. Nursing Research. 2013;62(5):315–324. Ineligible intervention.23995465
74 Corazzini KN, Mueller C, Anderson RA, Day L, Hunt-McKinney S, Porter K. PAIN MEDICATION MANAGEMENT in Nursing Homes and Nursing Scope of Practice. Journal of Gerontological Nursing. 2013;39(4):40–46. Ineligible study design.
75 Corazzini KN, Vogelsmeier A, McConnell ES, . Perceptions of Nursing Practice: Capacity for High-Quality Nursing Home Care. Journal of Nursing Regulation. 2015;6(3):17–24. No eligble outcomes.
76 Crecelius C. Determining the Physician-to-Patient Ratio in Post-Acute/Long-Term Care Using an Economic Model. Journal of the American Medical Directors Association. 2017;18(12):1088–1089. No eligble outcomes.29169737
77 Cummings GG, Estabrooks CA, Doupe M, Ginsburg L, McGregor MJ, Norton PG. Development and Validation of A Scheduled Shifts Staffing (ASSiST) Measure of Unit-Level Staffing in Nursing Homes. The Gerontologist. 2017;57(3):509–516. Ineligible setting.26884062
78 Currie LM. Fall and injury prevention. Annual Review of Nursing Research. 2006;24:39–74. Ineligible publication type.
79 Czarnowski EJ, Hickey EC, Young GJ, Parker VA, Berlowitz DR, Saliba D. The effects of changes in nursing home staffing on pressure ulcer rates. Journal of the American Medical Directors Association. 2005;6(1):50–53. No data 2000 or later.15871871
80 Daras LC, Vadnais A, Pogue YZ, . Nearly 1 in five skilled nursing facilities awarded positive incentives under value-based purchasing. Health Affairs. 2021;40(1):146–155. No data 2000 or later.33400571
81 Decker FH. Nursing staff and the outcomes of nursing home stays. Medical Care. 2006;44(9):812–821. No data 2000 or later.16932132
82 Decker FH. Nursing home performance in resident care in the United States: Is it only a matter of for-profit versus not-for-profit? Health Economics, Policy and Law. 2008;3(2):115–140. Ineligible intervention.18634624
83 Decker FH. The relationship of nursing staff to the hospitalization of nursing home residents. Research in nursing & health. 2008;31(3):238–251. No data 2000 or later.18228574
84 Degenholtz HB, Kane RA, Kane RL, . Predicting nursing facility residents’ quality of life using external indicators. Health Services Research. 2006;41(2):335–356. Ineligible intervention.16584452
85 Del Signore A. RNs More Likely to Spot Medication Discrepancies than LPNs. Annals of Long Term Care. 2016;24(1):37–38. Ineligible study design.27340375
86 Dellefield ME, Harrington C, Kelly A. Observing How RNs Use Clinical Time in a Nursing Home: A Pilot Study. Geriatric Nursing. 2012;33(4):256–263. No eligble outcomes.22341642
87 Dill JS, Morgan JC, Konrad TR. Strengthening the long-term care workforce: the influence of the WIN A STEP UP workplace intervention on the turnover of direct care workers. Journal of Applied Gerontology. 2010;29(2):196–214. Ineligible intervention.
88 Dilles T, Stichele RV, Van Rompaey B, Van Bortel L, Elseviers M. Nurses’ practices in pharmacotherapy and their association with educational level. Journal of Advanced Nursing. 2010;66(5):1072–1079. Ineligible setting.20337787
89 Dixon S, Kaambwa B, Nancarrow S, Martin GP, Bryan S. The relationship between staff skill mix, costs and outcomes in intermediate care services. BMC health services research. 2010;10:221. Ineligible setting.20670428
90 DuBeau C, Mazor KM, Field TS, . Are indwelling catheters truly a quality problem in long-term care? Journal of the American Geriatrics Society. 2015;63(SUPPL. 1):S103. Ineligible publication type.
91 Dyck MJ. Nursing staffing and resident outcomes in nursing homes: Weight loss and dehydration. Journal of Nursing Care Quality. 2007;22(1):59–65. Ineligible intervention.17149087
92 e Cordova PB, Johansen ML, Zha P, Prado J, Field V, Cadmus E. Does Public Reporting of Staffing Ratios and Nursing Home Compare Ratings Matter? Journal of the American Medical Directors Association. 2021. No eligble outcomes.
93 Eakman AM, Havens MD, Ager SJ, . Fall prevention in long-term care: an in-house interdisciplinary team approach. Topics in Geriatric Rehabilitation. 2002;17(3):29–39. No data 2000 or later.
94 Ersek M, Thorpe J, Kim H, Thomasson A, Smith D. Exploring End-of-Life Care in Veterans Affairs Community Living Centers. Journal of the American Geriatrics Society. 2015;63(4):644–650. Ineligible intervention.25809839
95 Estabrooks CA, Cummings GG, Kang SH, . The influence of organizational context on best practice use by care aides in residential long-term care settings. Journal of the American Medical Directors Association. 2015;16(6):e1–537. Ineligible setting.
96 Evans G. Factors influencing emergency hospital admissions from nursing and residential homes: Positive results from a practice-based audit. Journal of Evaluation in Clinical Practice. 2011;17(6):1045–1049. Ineligible intervention.20666882
97 Evans S, Redman J. Post Acute Readmissions? Not with your Nurse Practitioner in Charge! Journal of the American Medical Directors Association. 2020;21(3):B23–B24. Ineligible intervention.
98 Fain KM, Alexander GC, Dore DD, Segal JB, Zullo AR, Salgado C. Frequency and Predictors of Analgesic Prescribing in U.S. Nursing Home Residents with Persistent Pain. Journal of the American Geriatrics Society. 2017;65(2):286–293. No eligble outcomes.28198563
99 Fashaw SA, Thomas KS, McCreedy E, Mor V. Thirty-Year Trends in Nursing Home Composition and Quality Since the Passage of the Omnibus Reconciliation Act. Journal of the American Medical Directors Association. 2020;21(2):233–239. No eligble outcomes.31451383
100 Fehnel CR, Lee Y, Wendell LC, Thompson BB, Potter NS, Mor V. Post-Acute Care Data for Predicting Readmission After Ischemic Stroke: A Nationwide Cohort Analysis Using the Minimum Data Set. Journal of the American Heart Association. 2015;4(9):e002145-N.PAG. Ineligible intervention.26396202
101 Field TS, Gurwitz JH, Avorn J, . Risk factors for adverse drug events among nursing home residents. Archives of Internal Medicine. 2001;161(13):1629–1684. No data 2000 or later.11434795
102 Figueroa JF, Riley K, Zheng J, . Association of Nursing Home Ratings on Health Inspections, Quality of Care, and Nurse Staffing with COVID-19 Cases. JAMA - Journal of the American Medical Association. 2020;324(11):1103–1105. Ineligible intervention.32790822
103 Fike C, Drost J, Oravec M. Assessing the impact of Ohio’s STNA staffing ratio changes on long term care quality. Journal of the American Geriatrics Society. 2017;65(Supplement 1):S250–S251. Ineligible publication type.
104 Fleming AA, Day J, Glanfield L. Registered nurse management of urinary catheters in a rehabilitation and long-term care hospital. International Journal of Nursing Practice (Wiley-Blackwell). 2000;6(5):237–246. Ineligible setting.
105 Foltz C, Lawrence S, Bieiy N, Gratz N, Paxton H, Swavely D. Supporting Primary Care Patient-Centered Medical Homes with Community Care Teams: Findings from a Pilot Study. Journal of Clinical Outcomes Management. 2014;21(8):352–361. Ineligible intervention.
106 Foster AD, Lee YS. Staffing subsidies and the quality of care in nursing homes. Journal of health economics. 2015;41:133–147. Ineligible intervention.25814437
107 Frantz RA, Gardner S, Specht JK, McIntire G. Integration of pressure ulcer treatment protocol into practice: clinical outcomes and care environment attributes. Outcomes Management for Nursing Practice. 2001;5(3):112–120. No data 2000 or later.11898671
108 Ganz DA, Simmons SF, Schnelle JF. Cost-effectiveness of recommended nurse staffing levels for short-stay skilled nursing facility patients. BMC Health Services Research. 2005;5:35. Ineligible study design.15885148
109 Gauvin H. The Connecticut Nursing Home Quality Initiative--Part II. Connecticut medicine. 2003;67(4):245–246. Ineligible intervention.12760083
110 Goldfeld KS, Grabowski DC, Caudry DJ, Mitchell SL. Health insurance status and the care of nursing home residents with advanced dementia. JAMA Internal Medicine. 2013;173(22):2047–2053. Ineligible intervention.24061265
111 Good H, Riley-Doucet CK, Dunn KS. The Prevalence of Uncontrolled Pain in Long-Term Care. Journal of Gerontological Nursing. 2015;41(2):33–41. Ineligible intervention.25369582
112 Grabowski DC, Zhang X. Nursing Home Staffing and Quality under the Nursing Home Reform Act. Gerontologist. 2004;44(1):13–23. No data 2000 or later.14978317
113 Graham C, Bueno EB, Ross L, Harrington C. Assessing the Quality of Nursing Homes in Managed Care Organizations: Integrating LTSS for Dually Eligible Beneficiaries. Inquiry : a journal of medical care organization, provision and financing. 2018;55:46958018800090. Ineligible intervention.30222018
114 Gruber-Baldini AL, Zimmerman S, Boustani M, Watson LC, Williams CS, Reed PS. Characteristics associated with depression in long-term care residents with dementia. Gerontologist. 2005:50–55. Ineligible intervention.16230749
115 Hain DJ, Tappen R, Diaz S, Ouslander JG. Characteristics of older adults rehospitalized within 7 and 30 days of discharge: implications for nursing practice. Journal of gerontological nursing. 2012;38(8):32–44. Ineligible intervention.
116 Hanlon JT, Handler SM, Castle NG. Antidepressant prescribing in US nursing homes between 1996 and 2006 and its relationship to staffing patterns and use of other psychotropic medications. Journal of the American Medical Directors Association. 2010;11(5):320–324. No eligble outcomes.20511098
117 Harrington C. Nursing counts. CMS study: correlation between staffing and quality…Centers for Medicare and Medicaid Services (CMS). AJN American Journal of Nursing. 2002;102(9):65–66. Ineligible intervention.
118 Harrington C, Carrillo H, Kang T, Olney B. Nurse staffing and deficiencies in the largest for-profit nursing home chains and chains owned by private equity companies. Health Services Research. 2012;47(1 PART 1):106–128. Ineligible intervention.22091627
119 Harrington C, Ross L, Kang T. Hidden Owners, Hidden Profits, and Poor Nursing Home Care. International Journal of Health Services. 2015;45(4):779–800. Ineligible intervention.26159173
120 Harrington C, Woolhandler S, Mullan J, Carrillo H, Himmelstein DU. Does investor ownership of nursing homes compromise the quality of care? American Journal of Public Health. 2001;91(9):1452–1455. No data 2000 or later.11527781
121 Harrington C, Woolhandler S, Mullan J, Carrillo H, Himmelstein DU. Does investor-ownership of nursing homes compromise the quality of care? International Journal of Health Services. 2002;32(2):315–325. No data 2000 or later.12067034
122 Harris JA, Engberg J, Castle NG. Obesity and intensive staffing needs of nursing home residents. Geriatric nursing (New York, NY). 2018;39(6):696–701. Ineligible intervention.
123 Haun CN. Examining the Influence of Proximal Density to Nursing School Location on Quality Outcomes in Nursing Homes: An Expanded Study. Nursing Economic$. 2021;39(2):67–89. Ineligible intervention.
124 Heeren P, Van de Water G, De Paepe L, Boonen S, Vleugels A, Milisen K. Staffing Levels and the Use of Physical Restraints in Nursing Homes. Journal of Gerontological Nursing. 2014;40(12):48–54. Ineligible setting.
125 Hendrix TJ, Foreman SE. Optimal long-term care nurse-staffing levels. Nursing Economic$. 2001;19(4):164–175. No data 2000 or later.
126 Herzig CTA, Stone PW, Larson EL, Castle N, Pogorzelska-Maziarz M, Dick AW. Infection Prevention and Control Programs in US Nursing Homes: Results of a National Survey. Journal of the American Medical Directors Association. 2016;17(1):85–88. Ineligible intervention.26712489
127 Hickman SE, Unroe KT, Buente B, Nazir A, Sachs GA, Ersek MT. An Interim Analysis of an Advance Care Planning Intervention in the Nursing Home Setting. Journal of the American Geriatrics Society. 2016;64(11):2385–2392. Ineligible intervention.27676237
128 Hicks LL, Rantz MJ, Petroski GF, Mukamel DB. Nursing home costs and quality of care outcomes. Nursing Economic$. 2004;22(4):178–192. No data 2000 or later.15382393
129 Hodgkinson B, Haesler EJ, Nay R, O’Donnell MH, McAuliffe LP. Effectiveness of staffing models in residential, subacute, extended aged care settings on patient and staff outcomes. Cochrane Database of Systematic Reviews. 2011:N.PAG-N.PAG. Ineligible study design.
130 Hofmann MT, Bankes PF, Javed A, Selhat M. Decreasing the incidence of falls in the nursing home in a cost-conscious environment: A pilot study. Journal of the American Medical Directors Association. 2003;4(2):95–97. Ineligible intervention.12807581
131 Hofmann MT, Love R, Francis MA, Corkery EA, Ogunnubi O. A Multidisciplinary Process to Improve Quality Indicators in a Veterans Affairs Community Living Center. Journal of the American Medical Directors Association. 2020;21(3):B15. Ineligible intervention.
132 Holtz L, Hickman S, Tegeler M, Sachs G, Unroe K, Maurer H. Improving the quality of care to reduce avoidable hospitalizations of nursing facility residents: The optimistic project. Journal of Pain and Symptom Management. 2014;47(2):483–484. Ineligible intervention.
133 Horn SD. The business case for nursing in long-term care. Policy, politics & nursing practice. 2008;9(2):88–93. No data 2000 or later.
134 Horn SD, Bender SA, Ferguson ML, . The National Pressure Ulcer Long-Term Care Study: pressure ulcer development in long-term care residents. Journal of the American Geriatrics Society. 2004;52(3):359–367. No data 2000 or later.14962149
135 Horn SD, Buerhaus P, Bergstrom N, Smout RJ. RN staffing time and outcomes of long-stay nursing home residents: pressure ulcers and other adverse outcomes are less likely as RNs spend more time on direct patient care. The American journal of nursing. 2005;105(11):58–71. No data 2000 or later.
136 Horn SD, Smout RJ, Dorr DA. Cost analysis of nursing home registered nurse staffing times. Journal of the American Geriatrics Society. 2005;53(5):840–845. No data 2000 or later.15877561
137 Huang SS, Bowblis JR. Managerial Ownership in Nursing Homes: Staffing, Quality, and Financial Performance. The Gerontologist. 2018;58(6):1136–1146. Ineligible intervention.28637215
138 Huijben-Schoenmakers M, Rademaker A, Scherder E. Increasing therapy time by implementing four interventions from the clinical nursing rehabilitation stroke guideline. Cerebrovascular Diseases. 2017;43(Supplement 1):135. Ineligible intervention.
139 Hunnicutt JN, Jonggyu B, Alcusky M, . Geographic Variation in the Initiation of Commonly Used Opioids and Dosage Strength in United States Nursing Homes. Medical Care. 2018;56(10):847–854. Ineligible intervention.30113423
140 Hunnicutt JN, Ulbricht CM, Tjia J, Lapane KL. Pain and pharmacologic pain management in long-stay nursing home residents. PAIN. 2017;158(6):1091–1099. Ineligible intervention.28267065
141 Hunt SR, Corazzini K, Anderson RA. Top nurse-management staffing collapse and care quality in nursing homes. Journal of Applied Gerontology. 2014;33(1):51–74. Ineligible study design.24652943
142 Hurtado DA, Berkman LF, Buxton OM, Okechukwu CA. Schedule Control and Nursing Home Quality: Exploratory Evidence of a Psychosocial Predictor of Resident Care. Journal of applied gerontology : the official journal of the Southern Gerontological Society. 2016;35(2):244–253. Ineligible intervention.25186313
143 Hutt E, Frederickson E, Ecord M, Kramer AM. Associations among processes and outcomes of care for Medicare nursing home residents with acute heart failure. Journal of the American Medical Directors Association. 2003;4(4):195–199. No data 2000 or later.12837140
144 Hye-Young J, Qijuan L, Rahman M, Mor V. Medicare Advantage Enrollees’ Use of Nursing Homes: Trends and Nursing Home Characteristics. American Journal of Managed Care. 2018;24(8):e249–e256. No eligble outcomes.30130025
145 Hyer K, Temple A, Johnson CE. Florida’s efforts to improve quality of nursing home care through nurse staffing standards, regulation, and Medicaid reimbursement. Journal of aging & social policy. 2009;21(4):318–337. Ineligible intervention.20092125
146 Hyer K, Thomas KS, Branch LG, Harman JS, Johnson CE, Weech-Maldonado R. The influence of nurse staffing levels on quality of care in nursing homes. The Gerontologist. 2011;51(5):610–616. No eligble outcomes.21602292
147 Hyer K, Thomas KS, Johnson CE, Harman JS, Weech-Maldonado R. Do Medicaid Incentive Payments Boost Quality? Florida’s Direct Care Staffing Adjustment Program. Journal of Aging and Social Policy. 2013;25(1):65–82. No eligble outcomes.23256559
148 Ingber MJ, Feng Z, Khatutsky G, . Initiative To Reduce Avoidable Hospitalizations Among Nursing Facility Residents Shows Promising Results. Health affairs (Project Hope). 2017;36(3):441–450. Ineligible intervention.28264945
149 Intrator O, Castle NG, Mor V, Intrator O, Castle NG, Mor V. Facility characteristics associated with hospitalization of nursing home residents: results of a national study. Medical Care. 1999;37(3):228–237. No data 2000 or later.10098567
150 Intrator O, Zinn J, Mor V. Nursing home characteristics and potentially preventable hospitalizations of long-stay residents. Journal of the American Geriatrics Society. 2004;52(10):1730–1736. No data 2000 or later.15450053
151 Isaksson U. Factors associated with the prevalence of violent behaviour among residents living in nursing homes. Journal of Clinical Nursing (Wiley-Blackwell). 2009;18(7):972–980. Ineligible population.
152 Jesdale BM, Mack DS, Forrester SN, Lapane KL. Cancer Pain in Relation to Metropolitan Area Segregation and Nursing Home Racial and Ethnic Composition. Journal of the American Medical Directors Association. 2020;21(9):1302–1302. Ineligible intervention.32224259
153 Jester DJ, Hyer K, Bowblis JR. Quality Concerns in Nursing Homes That Serve Large Proportions of Residents With Serious Mental Illness. Gerontologist. 2020;60(7):1312–1321. Ineligible intervention.32474588
154 Jia H, Pei Q, Sullivan CT, . Poststroke Rehabilitation and Restorative Care Utilization: A Comparison Between VA Community Living Centers and VA-contracted Community Nursing Homes. Medical Care. 2016;54(3):235–242. Ineligible intervention.26807537
155 Jogerst GJ, Daly JM, Hartz AJ. State policies and nursing home characteristics associated with rates of resident mistreatment. Journal of the American Medical Directors Association. 2008;9(9):648–656. No eligble outcomes.18992697
156 Jogerst GJ, Daly JM, Schmuch G, Dawson JD, Peek-Asa C. Iowa Nursing Home Characteristics Associated With Reported Abuse. Journal of the American Medical Directors Association. 2006;7(4):203–207. Ineligible intervention.16698504
157 Jumaili AA, Doucette WR. A Systems Approach to Identify Factors Influencing Adverse Drug Events in Nursing Homes. Journal of the American Geriatrics Society. 2018;66(7):1420–1427. Ineligible intervention.29691843
158 Kane RL, Keckhafer G, Flood S, Bershadsky B, Siadaty S. The effect of Evercare on hospital use. Journal of the American Geriatrics Society. 2003;51(10):1427–1434. Ineligible intervention.14511163
159 Kang H, Khachadourian Y, Perella D, Peritz TM, Feemster KA, Coffin SE. The burden of gastroenteritis outbreaks in long-term care settings in Philadelphia, 2009-2018. Infection Control and Hospital Epidemiology. 2020;41(11):1310–1314. Ineligible population.32799937
160 Kang-Yi CD, Mandell DS, Mui AC, Castle NG. Interaction effect of Medicaid census and nursing home characteristics on quality of psychosocial care for residents. Health care management review. 2011;36(1):47–57. No eligble outcomes.21157230
161 Katz PR, Pfeil LA, Evans J, Evans M, Sobel H. Determining the Optimum Physician-to-Resident Ratio in the Nursing Home. Journal of the American Medical Directors Association. 2017;18(12):1087–1088. Ineligible study design.29108890
162 Keeler H, Baier RR, Kosar C, Culross B, Cramer ME. Examining the Impact of Board-Certified Registered Nurses in Skilled Nursing Facilities Using National and State Quality and Clinical Indicators. Journal of gerontological nursing. 2019;45(11):39–45. Ineligible intervention.
163 Kelly CM, Morgan JC, Jason KJ. Home care workers: Interstate differences in training requirements and their implications for quality. Journal of Applied Gerontology. 2013;32(7):804–832. Ineligible population.25474799
164 Kennedy A. Evaluating nursing staff mix in long-term care: a comprehensive framework for decision-makers. Healthcare quarterly (Toronto, Ont). 2009;12(4):46–53. Ineligible setting.20057229
165 Kim H, Harrington C, Greene WH. Registered nurse staffing mix and quality of care in nursing homes: A longitudinal analysis. Gerontologist. 2009;49(1):81–90. No eligble outcomes.19363006
166 Kim H, Kovner C, Harrington C, Greene W, Mezey M. A panel data analysis of the relationships of nursing home staffing levels and standards to regulatory deficiencies. The journals of gerontology Series B, Psychological sciences and social sciences. 2009;64(2):269–278. No eligble outcomes.19181692
167 Kim H, Whall AL. Factors associated with psychotropic drug usage among nursing home residents with dementia. Nursing Research. 2006;55(4):252–258. No eligble outcomes.16849977
168 Kim Y, Davidson LJ, Wolf GA, Wang S-L, Whitman GR. The impact of staffing on patient outcomes across specialty units. Journal of Nursing Administration. 2002;32(12):633–639. No data 2000 or later.12483084
169 Kimball CC, Nichols CI, Vose JG, Nunley RM, Stambough JB. Skilled Nursing Facility Star Rating, Patient Outcomes, and Readmission Risk After Total Joint Arthroplasty. Journal of Arthroplasty. 2018;33(10):3130–3137. No eligble outcomes.30001882
170 King BJ, Mody L, McNamara SE, . Comparing Catheter-Associated Urinary Tract Infection Prevention Programs between Veterans Affairs Nursing Homes and Non-Veterans Affairs Nursing Homes. Infection Control and Hospital Epidemiology. 2017;38(3):287–293. No eligble outcomes.27917728
171 Kinsley M. No pressure: as partners in a pressure ulcer prevention program, nurse leaders and staff aim high and achieve remarkable results at North Shore’s Extended Care and Rehabilitation. Nursing Spectrum -- New York & New Jersey Edition. 2008;20A(24):18–19. Ineligible publication type.
172 Kluger M. Nursing counts. Staff turnover in nursing homes: organizational characteristics were examined. AJN American Journal of Nursing. 2006;106(10):71–71. Ineligible study design.17016100
173 Konetzka RT, Park J, Ellis R, Abbo E. Malpractice litigation and nursing home quality of care. Health Services Research. 2013;48(6 PART1):1920–1938. No eligble outcomes.23741985
174 Konetzka RT, Yi D, Norton EC, Kilpatrick KE. Effects of medicare payment changes on nursing home staffing and deficiencies. Health Services Research. 2004;39(3):463–488. No data 2000 or later.15149474
175 Kovner CT, Harrington C. CMS study: correlation between staffing and quality. The American journal of nursing. 2002;102(9):65–66. No eligble outcomes.
176 Krishnakurup J, Argento V, Choksey M, Blagodatny M, Skudlarska B, Shukla S. Comparison of fall protocols between 2 skilled nursing facilities. Journal of the American Geriatrics Society. 2010;58(SUPPL. 1):S53. Ineligible publication type.
177 Lakey SL, Gray SL, Sales AEB, Sullivan J, Hedrick SC. Psychotropic use in community residential care facilities: A prospective cohort study. The American journal of geriatric pharmacotherapy. 2006;4(3):227–235. No data 2000 or later.17062323
178 Lane SJ, Troyer JL, Dienemann JA, Laditka SB, Blanchette CM. Effects of skilled nursing facility structure and process factors on medication errors during nursing home admission. Health care management review. 2014;39(4):340–351. Ineligible intervention.24153027
179 Lapane KL, Hughes CM, Lapane KL, Hughes CM. Which organizational characteristics are associated with increased management of depression using antidepressants in US nursing homes? Medical Care. 2004;42(10):992–1000. No eligble outcomes.15377932
180 Lee HYu, Shin JHy, Harrington C. Comparing the nurse staffing in Korean and U.S. nursing homes. Nursing outlook. 2015;63(2):137–143. No eligble outcomes.25261384
181 Lee S, Johnson J, Veeder H, Trinh HD, Sanchez-Reilly S. Evaluating impact of direct interdisciplinary team hours of care among hospice-enrolled older adults with terminal illness. Journal of the American Geriatrics Society. 2018;66(Supplement 2):S208–S209. Ineligible publication type.
182 Lemaitre M, Meret T, Rothan-Tondeur M, . Effect of influenza vaccination of nursing home staff on mortality of residents: a cluster-randomized trial. Journal of the American Geriatrics Society. 2009;57(9):1580–1586. Ineligible intervention.19682118
183 Lerner NB. The relationship between nursing staff levels, skill mix, and deficiencies in Maryland nursing homes. The health care manager. 2013;32(2):123–128. No eligble outcomes.23629034
184 Li Y, Cen X, Cai X, Greener H. Racial and Ethnic Disparities in COVID-19 Infections and Deaths Across U.S. Nursing Homes. Journal of the American Geriatrics Society. 2020;68(11):2454–2461. Ineligible intervention.32955105
185 Li Y, Cen X, Temkin-Greener H, Harrington C, Mukamel DB, Cai X. Nurse staffing hours at nursing homes with high concentrations of minority residents, 2001-11. Health Affairs. 2015;34(12):2129–2137. Ineligible intervention.26643634
186 Li Y, Tang Y, Li Q. Associations between Family Ratings on Experience with Care and Clinical Quality-of-Care Measures for Nursing Home Residents. Medical Care Research and Review. 2016;73(1):62–84. Ineligible intervention.26199288
187 Li Y, Ye Z, Cai X, Glance LG, Harrington C, Mukamel DB. Satisfaction with massachusetts nursing home care was generally high during 2005-09, with some variability across facilities. Health Affairs. 2013;32(8):1416–1425. No eligble outcomes.23918486
188 Lichtman JH, Leifheit-Limson E, Wang Y, Goldstein LB. Association between skilled nursing facility quality indicators and hospital readmissions after stroke. Stroke. 2016;47(SUPPL. 1). Ineligible intervention.
189 Liu L-F, Weng R-H, Wu J-Y. Exploring factors influencing residents’ health outcomes in long-term care facilities: 1-year follow-up using latent growth curve model. Quality of Life Research. 2014;23(9):2613–2627. Ineligible setting.24838907
190 Livingstone IH. Examining the Effects of Professional Non-nursing Staffing on Quality of Care in Nursing Homes. Examining the Effects of Professional Non-Nursing Staffing on Quality of Care in Nursing Homes. 2018:1–1. Ineligible intervention.
191 Lorentz M, Finnegan B. An investigation of the effects of a nonprofit agency’s investigations on quality of care in nursing homes. Nursing forum. 2013;48(2):82–88. Ineligible intervention.23600636
192 Lucas J, Gerhard T, Chakravarty S, Crystal S, Bowblis J. Antipsychotic use among nursing home residents. Pharmacoepidemiology and Drug Safety (PDS). 2009;18(S1):S143. Ineligible study design.
193 Ludwin BM, Meeks S. Predictors of antipsychotic medication use in nursing home residents. American Journal of Geriatric Psychiatry. 2013;21(3 SUPPL. 1):S117–S118. Ineligible study design.
194 Maas ML, Specht JP, Buckwalter KC, Gittler J, Bechen K. Nursing home staffing and training recommendations for promoting older adults’ quality of care and life: Part 2. Increasing nurse staffing and training. Research in gerontological nursing. 2008;1(2):134–152. Ineligible study design.20078026
195 Mangaco-Borja E. The significance of introducing permanent assignments for nursing assistants at a long-term care setting on the incidence rate of facility-acquired pressure ulcers among elderly patients. Journal of the American College of Certified Wound Specialists. 2011;3(1):13–15. Ineligible intervention.24527161
196 Mansbach WE, Mace RA, Clark KM, Firth IM, Breeden JK. Predicting Off-Label Antipsychotic Medication Use in a Randomly Selected Nursing Home Sample Based on Resident and Facility Characteristics. Research in Gerontological Nursing. 2016;9(6):257–266. Ineligible intervention.27665755
197 Mason DJ. Contrasts in long-term care [corrected] [published erratum appears in AM J NURS 2009 Mar;109(3):14]. AJN American Journal of Nursing. 2009;109(1):50–51. Ineligible study design.
198 Mathew R, Young Y, Shrestha S. Factors Associated With Potentially Preventable Hospitalization Among Nursing Home Residents in New York State With Chronic Kidney Disease. Journal of the American Medical Directors Association. 2012;13(4):337–343. Ineligible intervention.21450241
199 McCarthy EP, Ogarek JA, Loomer L, . Hospital Transfer Rates Among US Nursing Home Residents With Advanced Illness Before and After Initiatives to Reduce Hospitalizations. JAMA Internal Medicine. 2020;180(3):385–394. Ineligible intervention.31886827
200 McConnell ES, Lekan D, Corazzini KN. Assuring the adequacy of staffing of long-term care, strengthening the caregiving workforce, and making long-term care a career destination of choice: from mission impossible to mission critical? North Carolina medical journal. 2010;71(2):153–157. Ineligible study design.20552768
201 McDonald SM, Wagner LM, Castle NG. Staffing-Related Deficiency Citations in Nursing Homes. Journal of Aging and Social Policy. 2013;25(1):83–97. No eligble outcomes.23256560
202 McGarry BE, Grabowski DC, Barnett ML. Severe staffing and personal protective equipment shortages faced by nursing homes during the covid-19 pandemic. Health Affairs. 2020;39(10):1812–1821. No eligble outcomes.32816600
203 McGarry BE, White EM, Resnik LJ, Rahman M, Grabowski DC. Medicare’s new patient driven payment model resulted in reductions in therapy staffing in skilled nursing facilities. Health Affairs. 2021;40(3):392–399. No eligble outcomes.33646861
204 McMullen TL, Resnick B, Hansen JC, Miller N, Rubinstein R. Certified Nurse Aides and Scope of Practice: Clinical Outcomes and Patient Safety. Journal of gerontological nursing. 2015;41(12):32–39. Ineligible intervention.
205 McNulty CAM, Bowen J, Foy C, . Urinary catheterization in care homes for older people: self-reported questionnaire audit of catheter management by care home staff. The Journal of hospital infection. 2006;62(1):29–36. Ineligible setting.16309782
206 Merrifield N. Care homes in staffing crisis as nurses leave to work in NHS. Nursing times. 2015;111(28–29):4. Ineligible setting.
207 Miles RW. Hip fracture reduction in northwest Arkansas nursing homes. Journal of the American Medical Directors Association. 2008;9(6):449–453. Ineligible intervention.18585648
208 Miller EL, Alexander GL. Effects of Staffing and Regional Location on Influenza and Pneumococcal Vaccination Rates in Nursing Home Residents. Journal of Gerontological Nursing. 2016;42(2):38–44. No eligble outcomes.
209 Miller S, Looze J. Do us nursing homes “build or buy” their palliative care expertise? Journal of Pain and Symptom Management. 2012;43(2):339. Ineligible publication type.
210 Miller SC, Papandonatos G, Fennell M, Mor V. Facility and county effects on racial differences in nursing home quality indicators. Social Science & Medicine. 2006;63(12):3046–3059. No data 2000 or later.16997439
211 Min A, Hong HC. Effect of nurse staffing on rehospitalizations and emergency department visits among short-stay nursing home residents: A Cross-sectional study using the US Nursing Home Compare database. Geriatric nursing (New York, NY). 2019;40(2):160–165. Ineligible intervention.
212 Mitchell SL, Kiely DK, Gillick MR. Nursing home characteristics associated with tube feeding in advanced cognitive impairment. Journal of the American Geriatrics Society. 2003;51(1):75–79. No data 2000 or later.12534849
213 Mitchell SL, Teno JM, Intrator O, Feng Z, Mor V. Decisions to forgo hospitalization in advanced dementia: a nationwide study. Journal of the American Geriatrics Society. 2007;55(3):432–438. Ineligible intervention.17341248
214 Mody L, Greene MT, Meddings J, . A National Implementation Project to Prevent Catheter-Associated Urinary Tract Infection in Nursing Home Residents. JAMA Internal Medicine. 2017;177(8):1154–1162. Ineligible intervention.28525923
215 Morgan DJ, Zhan M, Goto M, . The Effectiveness of Contact Precautions on Methicillin-Resistant Staphylococcus aureus in Long-term Care Across the United States. Clinical Infectious Diseases. 2020;71(7):1676–1683. Ineligible intervention.31637429
216 Morley JE. Certified nursing assistants: A key to resident quality of life. Journal of the American Medical Directors Association. 2014;15(9):610–612. Ineligible study design.25086690
217 Moseley CB, Jones L. Registered nurse staffing and OBRA deficiencies in Nevada nursing facilities. Journal of gerontological nursing. 2003;29(3):44–50. No data 2000 or later.
218 Mount JK, Svarstad BL. Chronic benzodiazepine use in nursing homes: Effects of federal guidelines, resident mix, and nurse staffing. Journal of the American Geriatrics Society. 2001;49(12):1673–1678. No data 2000 or later.11844002
219 Mueller C. Nurse staffing in long-term care facilities. Journal of Nursing Administration. 2002;32(12):640–647. Ineligible study design.12483085
220 Mueller C, Karon SL. ANA nurse sensitive quality indicators for long-term care facilities. Journal of nursing care quality. 2004;19(1):39–47. Ineligible intervention.14717147
221 Mukamel DB, Kang T, Collier E, Harrington C. The relationship of California’s medicaid reimbursement system to nurse staffing levels. Medical Care. 2012;50(10):836–842. No eligble outcomes.22874499
222 Mukamel DB, Weimer DL, Harrington C, Spector WD, Ladd H, Li Y. The effect of state regulatory stringency on nursing home quality. Health Services Research. 2012;47(5):1791–1813. Ineligible intervention.22946859
223 Myers S, Castle NG. Mental health care deficiency citations in nursing homes and caregiver staffing. Administration and Policy in Mental Health and Mental Health Services Research. 2006;33(2):215–225. No data 2000 or later.16520903
224 Nazir A, Abrahamson K. Poise-care: A model of patient-centetred care in a skilled nursing facility. Journal of the American Geriatrics Society. 2015;63(SUPPL. 1):S73–S74. Ineligible intervention.
225 Needleman J. The Economic Case for Fundamental Nursing Care. Nursing Leadership (1910-622X). 2016;29(1):26–36. Ineligible intervention.27309639
226 Nelson R. AJN reports. Certified medication aides: do they free up nurses’ time? Or do they water down care? AJN American Journal of Nursing. 2005;105(9):28–29. Ineligible study design.
227 Nelson ST, Flynn L. Relationship between missed care and urinary tract infections in nursing homes. Geriatric Nursing. 2015;36(2):126–130. Ineligible intervention.25563066
228 Neylon J. Nurse-led management of chronic disease in a residential care setting. Nursing Older People. 2015;27(9):22–26. Ineligible setting.
229 Ogunneye O, Rothberg M, Gadiraju TV, Stefan M, Slawsky M, Friderici J. The association between nursing home care quality and 30-day readmission rates after hospitalization for heart failure. Journal of Cardiac Failure. 2012;18(8 SUPPL. 1):S4. Ineligible publication type.
230 Olsho LEW, Spector WD, Williams CS, . Evaluation of AHRQ’s On-Time Pressure Ulcer Prevention Program: A Facilitator-assisted Clinical Decision Support Intervention for Nursing Homes. Medical Care. 2014;52(3):258–266. Ineligible intervention.24374408
231 Omotowa OO. Staffing Standards and Care Outcomes in For-Profit and Not-For-Profit Religious-Based Nursing Homes. Staffing Standards & Care Outcomes in For-Profit & Not-For-Profit Religious-Based Nursing Homes. 2017:1–1. Ineligible publication type.
232 Ong ACL, Sabanathan K, Potter JF, Myint PK. High mortality of older patients admitted to hospital from care homes and insight into potential interventions to reduce hospital admissions from care homes: The Norfolk experience. Archives of Gerontology and Geriatrics. 2011;53(3):316–319. Ineligible setting.21194757
233 Orth J, Temkin-Greener H, Li Y, Simning A, Zimmerman S. Nursing home residents with dementia experience better end-of-life care and outcomes in nursing homes with Alzheimer’s special care units. Health Services Research. 2020;55(SUPPL 1):19. Ineligible publication type.
234 Pagel PJ, Vollbrecht M, Beyers D, Garcia S, Soryal S, Malone M. Transitions from acute care for elders: A readmission reduction program. Journal of the American Geriatrics Society. 2013;61(SUPPL. 1):S59–S60. Ineligible intervention.
235 Pakai A, Havasi-Santha E, Mate O, . Influence of cognitive function and nurse support on malnutrition risk in nursing home residents. Nursing open. 2021. Ineligible setting.
236 Park J, Stearns SC. Effects of state minimum staffing standards on nursing home staffing and quality of care. Health services research. 2009;44(1):56–78. Ineligible intervention.18823448
237 Patterson J. The effects of nurse to patient ratios. Nursing times. 2011;107(2):22–25. Ineligible study design.
238 Paulus ATG, van Raak A, Keijzer F. Informal and formal caregivers’ involvement in nursing home care activities: impact of integrated care. Journal of Advanced Nursing (Wiley-Blackwell). 2005;49(4):354–366. Ineligible setting.
239 Plotzke M, Teno J, Ng Harrison Z, Patel A. How frequently do skilled visits occur during the last 2 days of life for medicare beneficiaries? Journal of Pain and Symptom Management. 2014;47(2):498–499. Ineligible study design.
240 Popham C, Orrell M. What matters for people with dementia in care homes? Aging & mental health. 2012;16(2):181–188. Ineligible study design.22129467
241 Potter DEB, Shaffer T, Correa-De-Araujo R, Rhona Limcangco M, Spector W. Risk factors associated with the occurrence of fractures in U.S. nursing homes: Resident and facility characteristics and prescription medications. Journal of the American Geriatrics Society. 2007;55(3):327–333. No data 2000 or later.17341233
242 Pradhan R, Weech-Maldonado R, Harman JS, Al-Amin M, Hyer K. Private equity ownership of nursing homes: Implications for quality. Journal of Health Care Finance. 2015;42(2). Ineligible intervention.
243 Prentice TC, Curley AL, Haas DC. Heart failure 30-day readmission rates are associated with nurse-patient ratios. Journal of Cardiac Failure. 2013;19(8 SUPPL. 1):S81. Ineligible study design.
244 Priest D. Nursing counts. NPs in nursing homes: an issue of quality. AJN American Journal of Nursing. 2004;104(9):71–71. Ineligible publication type.
245 Pronych GJ, Brown EJ, Mercer K, Horsch K. Oral health coordinators in long-term care - A pilot study. Special Care in Dentistry. 2010;30(2):59–65. No eligble outcomes.20415802
246 Prusynski R, Mroz T. Employment of Therapy Assistants and Quality in Skilled Nursing Facilities. Archives of Physical Medicine and Rehabilitation. 2020;101(12):e138. Ineligible publication type.
247 Putallaz P, Bosshard W, Bula C, Papadimitriou M, Senn L. Nosocomial spread of SARS-CoV-2 in a rehabilitation facility: The silent threat of asymptomatic patients with high viral load? European Geriatric Medicine. 2020;11(SUPPL 1):S10. Ineligible intervention.
248 Radcliff TA, Liebrecht D, Fish R, McNulty M, Kramer AM, Hutt E. Associations among nurse and certified nursing assistant hours per resident per day and adherence to guidelines for treating nursing home-acquired pneumonia. Journals of Gerontology - Series A Biological Sciences and Medical Sciences. 2008;63(10):1105–1111. No eligble outcomes.18948562
249 Randolph PK, Scott-Cawiezell J. Developing a statewide medication technician pilot program in nursing homes. Journal of gerontological nursing. 2010;36(9):36–44. Ineligible intervention.20438012
250 Rantz MJ, Flesner MK, Franklin J, . Better Care, Better Quality: Reducing Avoidable Hospitalizations of Nursing Home Residents. Journal of nursing care quality. 2015;30(4):290–297. Ineligible intervention.26274511
251 Rantz MJ, Flesner MK, Zwygart-Stauffacher M. Improving care in nursing homes using quality measures/indicators and complexity science. Journal of nursing care quality. 2010;25(1):5–12. No eligble outcomes.20010251
252 Rantz MJ, Hicks L, Grando V, . Nursing home quality, cost, staffing, and staff mix. The Gerontologist. 2004;44(1):24–38. No eligble outcomes.14978318
253 Rantz MJ, Zwygart-Stauffacher M, Hicks L, . Randomized Multilevel Intervention to Improve Outcomes of Residents in Nursing Homes in Need of Improvement. Journal of the American Medical Directors Association. 2012;13(1):60–68. Ineligible intervention.21816681
254 Reid RC, Chappell NL. Staff ratios and resident outcomes in special care units: do activity aides make a difference? Journal of Applied Gerontology. 2003;22(1):89–103. No data 2000 or later.
255 Ritchie L. Unregulated staff administering medications. Nursing New Zealand (Wellington, NZ : 1995). 2012;18(10):30. Ineligible population.
256 Rosebush CE, Ramirez M, McGovern PM, . Evaluation of the Minnesota Safe Patient Handling Act: Trends in workers’ compensation indemnity claims in nursing home workers before and after enactment of the law. Occupational and Environmental Medicine. 2021;78(1):22–28. No eligble outcomes.32895318
257 Roup BJ, Roche JC, Pass M. Infection control program disparities between acute and long-term care facilities in Maryland. American Journal of Infection Control. 2006;34(3):122–127. No eligble outcomes.16630974
258 Russell TL, Madsen RW, Flesner M, Rantz MJ. Pain management in nursing homes: what do quality measure scores tell us? Journal of Gerontological Nursing. 2010;36(12):49–56. Ineligible intervention.
259 Schiamberg LB, Oehmke J, Zhang Z, . Physical abuse of older adults in nursing homes: a random sample survey of adults with an elderly family member in a nursing home. Journal of elder abuse & neglect. 2012;24(1):65–83. Ineligible intervention.22206513
260 Schnelle JF. Determining the relationship between staffing and quality. The Gerontologist. 2004;44(1):10–12. Ineligible publication type.14978316
261 Schnelle JF, Karuza J, Katz PR. Staffing, quality, and productivity in the nursing home. Journal of the American Medical Directors Association. 2013;14(11):784–786. Ineligible study design.24094900
262 Schnelle JF, Simmons SF. Individualized feeding assistance care for nursing home residents: Staffing requirements to implement 2 interventions. Journals of Gerontology - Series A Biological Sciences and Medical Sciences. 2004;59(9):966–973. Ineligible intervention.
263 Schnelle JF, Simmons SF, Schroyer LD, Saraf AA. Determining Nurse Aide Staffing Requirements to Provide Care Based on Resident Workload: A Discrete Event Simulation Model. Journal of the American Medical Directors Association. 2016;17(11):970–977. Ineligible intervention.27780572
264 Sharkey SS, Hudak S, Horn SD, James B, Howes J. Frontline caregiver daily practices: A comparison study of traditional nursing homes and the green house project sites. Journal of the American Geriatrics Society. 2011;59(1):126–131. No eligble outcomes.21158746
265 Shaw PA. Nursing assistants and quality nursing home care. Journal of the American Medical Directors Association. 2014;15(9):609. Ineligible publication type.25037170
266 Shefer A, McKibben L, Bardenheier B, Bratzler D, Roberts H. Characteristics of long-term care facilities associated with standing order programs to deliver influenza and pneumococcal vaccinations to residents in 13 states. Journal of the American Medical Directors Association. 2005;6(2):97–104. Ineligible intervention.15871883
267 Sheikh F, Elon RD, Katz MJ, Brandt N. COVID-19 Pandemic and Management of Chronic Pain in Nursing Homes. Journal of the American Medical Directors Association. 2021;22(3):518–519. Ineligible study design.33549561
268 Shin JH. Why Do We Require Registered Nurses in Nursing Homes? Using Longitudinal Hierarchical Linear Modeling. Journal of nursing scholarship : an official publication of Sigma Theta Tau International Honor Society of Nursing. 2018;50(6):705–713. Ineligible setting.30043547
269 Simmons SF, Durkin DW, Rahman AN, Choi L, Beuscher L, Schnelle JF. Resident Characteristics Related to the Lack of Morning Care Provision in Long-term Care. Gerontologist. 2013;53(1):151–161. No eligble outcomes.22565494
270 Simmons SF, Garcia E, Bates-Jensen BM, Schnelle JF, Harrington C, Cadogan M. Relationship of Nursing Home Staffing to Quality of Care. Health Services Research. 2004;39(2):225–250. No eligble outcomes.15032952
271 Sloane PD, Burkhart JI. Loving and lamenting the role of medications in long term care. Journal of the American Medical Directors Association. 2013;14(6):384–385. Ineligible study design.23764208
272 Smith DB, Feng Z, Fennell ML, Zinn JS, Mor V. Separate and unequal: racial segregation and disparities in quality across U.S. nursing homes. Health Affairs. 2007;26(5):1448–1458. Ineligible intervention.17848457
273 Sofer D. Proposed Regulations for Long-Term Care Omit Nurse Staffing Mandates. AJN American Journal of Nursing. 2017;117(2):12–12. Ineligible publication type.
274 Stearns SC, Park J, Zimmerman S, Gruber-Baldini AL, Konrad TR, Sloane PD. Determinants and effects of nurse staffing intensity and skill mix in residential care/assisted living settings. The Gerontologist. 2007;47(5):662–671. Ineligible population.17989408
275 Stephens TK. The Relationship between Nurse Staffing and Quality Outcomes in Georgia Nursing Homes. Relationship Between Nurse Staffing & Quality Outcomes In Georgia Nursing Homes. 2018:1–1. Ineligible publication type.
276 Stevenson DG. Nursing home consumer complaints and their potential role in assessing quality of care. Medical Care. 2005;43(2):102–111. No eligble outcomes.15655423
277 Stevenson DG, Bramson JS, Grabowski DC. Nursing Home Ownership Trends and Their Impacts on Quality of Care: A Study Using Detailed Ownership Data From Texas. Journal of Aging & Social Policy. 2013;25(1):30–47. Ineligible intervention.23256557
278 Stokes JA, Purdie DM, Roberts MS. Factors influencing PRN medication use in nursing homes. Pharmacy world & science : PWS. 2004;26(3):148–154. Ineligible setting.15230362
279 Stone R. Strengthening Care Staff in the Long-Term Care Sector: International Research Perspectives. Journal of Applied Gerontology. 2019;38(11):1515–1517. Ineligible publication type.31416378
280 Strumpf NE, Evans LK, Maislin G, Bourbonniere M. Organizational characteristics and restraint use for hospitalized nursing home residents. Journal of the American Geriatrics Society. 2003;51(8):1079–1084. No data 2000 or later.12890069
281 Svarstad BL, Mount JK, Bigelow W. Variations in the treatment culture of nursing homes and responses to regulations to reduce drug use. Psychiatric Services. 2001;52(5):666–672. No data 2000 or later.11331803
282 Tchouaket É, Kilpatrick K, Jabbour M. Effectiveness for introducing nurse practitioners in six long-term care facilities in Québec, Canada: A cost-savings analysis. Nursing Outlook. 2020;68(5):611–625. Ineligible setting.32713732
283 Temkin-Greener H, Mao Y, Ladwig S, McGarry B, Li Y. State variations in regulatory stringency for assisted living communities: Potential implications for service supply, cost, and quality. Health Services Research. 2020;55(SUPPL 1):23. Ineligible setting.
284 Thomas KS, Mor V, Tyler DA, Hyer K. The relationships among licensed nurse turnover, retention, and rehospitalization of nursing home residents. The Gerontologist. 2013;53(2):211–221. Ineligible intervention.22936529
285 Thompson DL. Geriatric incontinence: the long-term care challenge. Urologic Nursing. 2004;24(4):305–356. No data 2000 or later.15446379
286 Tjia J, Briesacher BA, Mazor KM, . Variation in nursing home antipsychotic use across psychiatric consultant providers. Pharmacoepidemiology and Drug Safety. 2013;22(SUPPL. 1):428–429. Ineligible study design.
287 Tjia J, Field TS, Mazor KM, . Dementia and risk of adverse warfarin-related events in the nursing home setting. Pharmacoepidemiology and Drug Safety. 2011;20(SUPPL. 1):S303. Ineligible study design.
288 Tolson D, Jackson GA, Dewar B. Quality of Life and Care in the Nursing Home. Journal of the American Medical Directors Association. 2014;15(3):154–157. Ineligible study design.24513224
289 Towsley GL, Beck SL, Pepper GA. Predictors of Quality in Rural Nursing Homes Using Standard and Novel Methods. Research in Gerontological Nursing. 2013;6(2):116–126. No eligble outcomes.23330834
290 Travers JL, Wu B, Agarwal M, . Assessment of Coronavirus Disease 2019 Infection and Mortality Rates Among Nursing Homes With Different Proportions of Black Residents. Journal of the American Medical Directors Association. 2021;22(4):893. Ineligible intervention.33762185
291 Trigilia D, Houle TL, Rosenblum D, Milne CT, Delong S. Reducing pressure ulcer prevalence rates in the long-term acute care Setting. Ostomy Wound Management. 2009;55(4):50–59. Ineligible intervention.
292 Trompelt J, Sauer O, Sturer A. Enquiries from nursing homes-increasing problems? Clinical Toxicology. 2014;52(SUPPL. 1):327. Ineligible study design.
293 Troyer JL, Sause W. Association between traditional nursing home quality measures and 2 sources of nursing home complaints. Health Services Research. 2013;48(4):1256–1278. Ineligible intervention.23216541
294 Tsan L, Davis C, Langberg R, Pierce JR. Quality indicators in the department of veterans affairs nursing home care units: a preliminary assessment. American Journal of Medical Quality. 2007;22(5):344–350. Ineligible intervention.17804394
295 Tyler DA, Leland N, Miller SC, Lepore M. Effect of increased nursing home hospice use on nursing assistant staffing. Journal of Palliative Medicine. 2011;14(11):1236–1239. Ineligible intervention.21958012
296 Uchida-Nakakoji M, Stone PW, Schmitt S, Phibbs C, Wang YC. Economic evaluation of registered nurse tenure on nursing home resident outcomes. Applied nursing research : ANR. 2016;29:89–95. Ineligible study design.26856495
297 Vadnais AJ, Vreeland E, Coomer NM, Feng Z, Ingber MJ. Reducing Transfers among Long-Stay Nursing Facility Residents to Acute Care Settings: Effect of the 2013–2016 Centers for Medicare and Medicaid Services Initiative. Journal of the American Medical Directors Association. 2020;21(9):1341–1345. Ineligible intervention.32146040
298 Van Der Spek K, Wetzels RB, Smeets CH, . Factors associated with appropriate psychotropic drug prescription in nursing home patients with severe dementia. International Psychogeriatrics. 2018;30(4):547–556. Ineligible population.28931452
299 Vig EK, Gessert CE, Haller IV. What is the true association between nursing home location and hospitalization of its residents?…Gessert CE, Haller IV, Kane RL et al. Rural-urban differences in medical care for nursing home residents with severe dementia at the end of life. J Am Geriatr Soc 2006;54:1199-1205. Journal of the American Geriatrics Society. 2007;55(3):471–473. Ineligible study design.17341257
300 Vogelsmeier A, Anbari A, Ganong L, . Detecting Medication Order Discrepancies in Nursing Homes: How RNs and LPNs Differ. Journal of Nursing Regulation. 2015;6(3):48–56. Ineligible intervention.
301 Voyer P, McCusker J, Cole MG, . Nursing documentation in long-term care settings: New empirical evidence demands changes be made. Clinical nursing research. 2014;23(4):442–461. Ineligible setting.23431024
302 Wachterman M, Marcantonio E, Davis R, McCarthy E. The effect of profit status on hospice: Results from the 2007 national home and hospice care survey. Journal of General Internal Medicine. 2010;25(SUPPL. 3):S402–S403. Ineligible publication type.
303 Walsh JE, Lane SJ, Troyer JL. Impact of medication aide use on skilled nursing facility quality. The Gerontologist. 2014;54(6):976–988. Ineligible intervention.23969257
304 Wan TTH. Nursing Care Quality in Nursing Homes: Cross-Sectional Versus Longitudinal Analysis. Journal of Medical Systems. 2003;27(3):283–295. No data 2000 or later.12705460
305 Wan TTH, Zhang NJ, Unruh L. Predictors of resident outcome improvement in nursing homes. Western Journal of Nursing Research. 2006;28(8):974–993. No eligble outcomes.17099108
306 Wang H, Ryskina KL, Yun H, Jung H-Y, Chen AT. Characteristics of Nursing Homes by COVID-19 Cases Among Staff: March to August 2020. Journal of the American Medical Directors Association. 2021;22(5):960. Ineligible intervention.33705743
307 Weech-Maldonado R, Meret-Hanke L, Neff MC, Mor V. Nurse staffing patterns and quality of care in nursing homes. Health Care Management Review. 2004;29(2):107–116. No data 2000 or later.15192983
308 Weech-Maldonado R, Pradhan R, Dayama N, Lord J, Gupta S. Nursing Home Quality and Financial Performance: Is There a Business Case for Quality? Inquiry : a journal of medical care organization, provision and financing. 2019;56:46958018825191. No eligble outcomes.30739511
309 Weinberg AD, Lesesne AJ, Richards CL, Pals JK. Quality care indicators and staffing levels in a nursing facility subacute unit. Journal of the American Medical Directors Association. 2002;3(1):1–4. Ineligible intervention.12807556
310 Wendelboe AM, Avery C, Andrade B, Baumbach J, Landen MG. Importance of employee vaccination against influenza in preventing cases in long-term care facilities. Infection Control & Hospital Epidemiology. 2011;32(10):990–997. Ineligible intervention.21931249
311 Werner RM, Konetzka RT, Polsky D. The effect of pay-for-performance in nursing homes: Evidence from state medicaid programs. Health Services Research. 2013;48(4):1393–1414. Ineligible intervention.23398330
312 While A. Lessons from the Evercare evaluation. British journal of community nursing. 2007;12(1):46. Ineligible study design.17353812
313 White EM, Kosar CM, Feifer RA, . Variation in SARS-CoV-2 Prevalence in U.S. Skilled Nursing Facilities. Journal of the American Geriatrics Society. 2020;68(10):2167–2173. Ineligible intervention.32674223
314 Winblad U, Blomqvist P, Karlsson A. Do public nursing home care providers deliver higher quality than private providers? Evidence from Sweden. BMC Health Services Research. 2017;17:1–12. Ineligible setting.28049468
315 Wipke-Tevis DD, Williams DA, Rantz MJ, . Nursing home quality and pressure ulcer prevention and management practices. Journal of the American Geriatrics Society. 2004;52(4):583–588. No data 2000 or later.15066075
316 Wowchuk SM, McClement S, Bond J. The challenge of providing palliative care in the nursing home part II: internal factors. International Journal of Palliative Nursing. 2007;13(7):345–350. Ineligible publication type.17851378
317 Yang BK, Carter MW, Nelson HW, Trinkoff AM. Nurse Staffing and Skill Mix Patterns in Relation to Resident Care Outcomes in US Nursing Homes. Journal of the American Medical Directors Association. 2021;22(5):1081. Ineligible intervention.33132015
318 Yoon JY, Lee JY, Bowers BJ, Zimmerman DR. The impact of organizational factors on the urinary incontinence care quality in long-term care hospitals: a longitudinal correlational study. International journal of nursing studies. 2012;49(12):1544–1551. Ineligible setting.22858237
319 You K, Li Y, Intrator O, . Do nursing home chain size and proprietary status affect experiences with care? Medical Care. 2016;54(3):229–234. Ineligible intervention.26765147
320 Young Y, Hannan EL, Barhydt NR, Broderick S, Colello AD. Factors associated with potentially preventable hospitalization in nursing home residents in New York state: A survey of directors of nursing. Journal of the American Geriatrics Society. 2010;58(5):901–907. Ineligible intervention.20406315
321 Young Y, Inamdar S, Dichter BS, Kilburn H, Jr H. Clinical and nonclinical factors associated with potentially preventable hospitalizations among nursing home residents in New York State. Journal of the American Medical Directors Association. 2011;12(5):364–371. Ineligible intervention.21450173
322 Yu K, Huey-Ming T, Miller NA. Facility Characteristics and Risk of Developing Pressure Ulcers in US Nursing Homes. Journal of Nursing Care Quality. 2016;31(1):E9–E16. Ineligible intervention.26121056
323 Yuan Y, Lapane KL, Baek J, Jesdale BM, Ulbricht CM. Nursing Home Star Ratings and New Onset of Depression in Long-Stay Nursing Home Residents. Journal of the American Medical Directors Association. 2019;20(10):1335–1335. Ineligible intervention.31281113
324 Yue L, Harrington C, Temkin-Greener H, . Deficiencies In Care At Nursing Homes And Racial/Ethnic Disparities Across Homes Fell, 2006-11. Health Affairs. 2015;34(7):1139–1146. No eligble outcomes.26153308
325 Yue L, Xueya C, Zhiqiu Y, Glance LG, Harrington C, Mukamel DB. Satisfaction With Massachusetts Nursing Home Care Was Generally High During 2005-09, With Some Variability Across. Health Affairs. 2013;32(8):1416–1425. Ineligible intervention.23918486
326 Zhang N, Li Y, Temkin-Greener H. Prevalence of Obesity in New York Nursing Homes: Associations With Facility Characteristics. Gerontologist. 2013;53(4):567–581. No eligble outcomes.23480892
327 Zhang NJ, Unruh L, Wan TTH. Gaps in nurse staffng and nursing home resident needs. Nursing economic$. 2013;31(6):289–297. Ineligible intervention.24592533
328 Zhang NJ, Wan TTH. Effects of institutional mechanisms on nursing home quality. Journal of health and human services administration. 2007;29(4):380–408. Ineligible intervention.17571466
329 Zhao M, Haley DR. Nursing home quality, staffing, and malpractice paid-losses. Journal of Health Care Finance. 2011;38(1):1–10. No eligble outcomes.
330 Zheng NT, Temkin-Greener H. End-of-life care in nursing homes: The importance of CNA staff Communication. Journal of the American Medical Directors Association. 2010;11(7):494–499. Ineligible intervention.20816337
331 Zimmaro Bliss D, Zehrer C, Savik K, Thayer D, Smith G. Incontinence-associated skin damage in nursing home residents: a secondary analysis of a prospective, multicenter study. Ostomy/wound management. 2006;52(12):46–55. Ineligible intervention.
332 Zimmerman S, Gruber-Baldini AL, Hebel JR, Sloane PD, Magaziner J. Nursing home facility risk factors for infection and hospitalization: importance of registered nurse turnover, administration, and social factors. Journal of the American Geriatrics Society. 2002;50(12):1987–1995. No data 2000 or later.12473010
333 Zimmerman S, Magaziner J, Birge SJ, Barton BA, Kronsberg SS, Kiel DP. Adherence to hip protectors and implications for U.S. long-term care settings. Journal of the American Medical Directors Association. 2010;11(2):106–115. Ineligible intervention.20142065
334 Zuidema SU, Koopmans RTCM, De Jonghe JFM, Verhey FRJ. Psychotropic drug prescription in nursing home patients with dementia: Influence of environmental correlates and staff distress on physicians’ prescription behavior. International Psychogeriatrics. 2011;23(10):1632–1639. Ineligible setting.21813036