# APPENDIX A SEARCH STRATEGIES

## MEDLINE

1 | Long term care/
2 | Exp nursing homes/
3 | Exp homes for the aged/
4 | ((senior* or continuity care or disabled or old age or geriatric* or elder care*) adj2 (lodge* or facility* or home* or residence* or centre* or center*)).mp.
5 | Or/1-4
6 | Nurses/or nurse administrators/ or nurse clinicians/ or nursing staff/ or licensed practical nurses/ or nursing assistants
7 | workload/or shift work schedule/
8 | nursing/ or nursing administration research/
9 | ((((RN or staff* or care or case or nurse* or skill) adj1 mix) or (staffing adj1model* or care model*) or ((nurs* or staff* or patient* or client) adj1 ratio*) or (nursing adj1 delivery systems$1) or (staff* adj1 level*) or (nurs* adj1 (availb* or coverage or presence or hours or role or dose or schedul* or workforce)) or (minute* or hour* or time)) adj1 (patient* or client* or resident*)).ti,ab.
10 | OR/6-9
11 | 5 and 10
12 | Limit 11 to English
13 | Limit 12 to yr=“2001-current”
14 | Limit 12 to yr=“2013 – current”

## EMBASE

1 | Institutional care/
2 | Nursing home patient/
3 | Exp nursing homes/
4 | Exp homes for the aged/
5 | ((senior* OR continuity care OR disabled OR old age OR geriatric* OR elder care*) ADJ2 (lodge* OR facility* OR home* OR residence* OR centre* OR center*)).mp.
6 | Or/1-5
7 | Nurse/or nurse administrator/ or clinical nurse specialist/ or nursing staff/ or nursing assistants/
8 | workload/or shift schedule/
9 | ((RN OR staff* OR care OR case OR nurse* OR skill) ADJ1 mix) OR (staffing ADJ1 model* OR care model*) OR ((nurs* OR staff* OR patient* OR client) ADJ1 ratio*) OR (nursing ADJ1 delivery systems$1) OR (staff* ADJ1 level*) OR (nurs* ADJ1 (availb* OR coverage OR presence OR hours OR role OR dose)) OR ( minute* OR hour* OR time) ADJ1 (patient* OR client* OR resident*)
10 | OR/7-9
11 | 6 and 10
12 | Limit 11 to English
13 | Limit 12 to yr=“2001-current”
14 | Limit 12 to yr=“2013-current”

## CINAHL

1 | MH “long term care”
2 | MH “nursing homes”
3 | TI ((senior* OR “continuity care” OR disabled OR “old age” OR geriatric* OR “elder care*”) N2 (lodge* OR facility* OR home* OR residence* OR centre* OR center*))
4 | AB ((senior* OR “continuity care” OR disabled OR “old age” OR geriatric* OR “elder care*”) N2 (lodge* OR facility* OR home* OR residence* OR centre* OR center*))
5 | S1 OR S2 OR S3 OR S4
6 | (MH “Nurses”) OR (MH “clinical nurse specialists”) OR (MH “practical nurses") OR “nursing assistants”
7 | MH “workload”
8 | MH nursing administration research
9 | TI ((RN OR staff* OR care OR case OR nurse* OR skill) N1 mix) OR (“staffing” N1 “model*” OR “care model*”) OR ((nurs* OR staff* OR patient* OR client) N1 ratio*) OR (nursing N1 “delivery systems*1”) OR (staff* N1 level*) OR (nurs* N1 (availb* OR coverage OR presence OR hours OR role OR dose)) OR (minute* OR hour* OR time) N1 (patient* OR client* OR resident*)
10 | AB ((RN OR staff* OR care OR case OR nurse* OR skill) N1 mix) OR (“staffing” N1 “model*” OR “care model*”) OR ((nurs* OR staff* OR patient* OR client) N1 ratio*) OR (nursing N1 “delivery systems*1”) OR (staff* N1 level*) OR (nurs* N1 (availb* OR coverage OR presence OR hours OR role OR dose)) OR (minute* OR hour* OR time) N1 (patient* OR client* OR resident*)
11 | S6 OR S7 OR S8 OR S9 OR S10
12 | S5 AND S11
13 | English (use the LA language field)
14 | EM 200101- (limits to Jan 2001 to present)
15 | EM 201301- (limits to Jan 2013 to present)

## GREY LITERATURE

Site | Date of Access | Terms
Centers for Medicare and Medicaid services; www.cms.gov | 9-15-2021 | “staffing levels”
Centers for Disease Control; www.cdc.gov | 9-15-2021 | “staffing levels” as exact phrase; “nursing home, long term care, community living center” as any of these words
American Association of Retired Persons; www.aarp.org | 9-14-2021 | “staffing levels”
American Health Care Association/National Center for Assisted Living; Ahcancal.org | 9-14-2021 | “staffing levels”; “nursing home” and filtered by content type of “AHCA Report”
Office of the Assistant Secretary for Planning and Evaluation; https://aspe.hhs.gov/ | 9-8-2021 | “nursing home” and filtered by topic of “Nursing Home and Facilities”; “staffing levels” and filtered by topic of “Long-Term Services & Supports, Long-Term Care”
American Nurses Association; Nursingworld.org | 9-10-2021 | “staffing levels”
Leading age; https://www.leadingagemn.org/ | 9-13-2021 | “nursing home”
McKnight; https://www.mcknight.org/ | 9-10-2021 | “nursing home”
Pioneer Network; https://www.pioneernetwork.net/ | 9-10-2021 | “nursing home”
Gerontological Society of America; https://www.geron.org/ | 9-10-2021 | “nursing home”
American Association of Colleges of Nursing; https://www.aacnnursing.org/ | 9-10-2021 | “nursing home”
Kaiser Family Foundation; https://www.kff.org/ | 9-13-2021 | “nursing home” and filtered by content type of “report”