# REFERENCES

1 Siegel RL, Miller KD, Wagle NS, Jemal A. Cancer statistics, 2023. CA Cancer J Clin. Jan 2023;73(1):17–48. doi:10.3322/caac.21763 36633525
2 Potter AL, Rosenstein AL, Kiang MV, Association of computed tomography screening with lung cancer stage shift and survival in the United States: quasi-experimental study. BMJ. Mar 30 2022;376:e069008. doi:10.1136/bmj-2021-069008
3 Franchio C. Help va spread awareness about lung cancer symptoms and screening. 2021. https://blogs.va.gov/VAntage/97439/help-va-spread-awareness-about-lung-cancer-symptoms-and-screening
4 Tandberg DJ, Tong BC, Ackerson BG, Kelsey CR. Surgery versus stereotactic body radiation therapy for stage I non-small cell lung cancer: A comprehensive review. Cancer. Feb 15 2018;124(4):667–678. doi:10.1002/cncr.31196 29266226
5 U. S. Preventive Services Task Force, Krist AH, Davidson KW, Screening for Lung Cancer: US Preventive Services Task Force Recommendation Statement. JAMA. Mar 9 2021;325(10):962–970. doi:10.1001/jama.2021.1117 33687470
6 (CSP) VCSP. CSP #2005 Surgery or Stereotactic Radiotherapy for Early-Stage Lung Cancer. Updated March 2021. https://www.vacsp.research.va.gov/CSP_2005/CSP_2005.asp
7 Lapen K, Mathis N.J., Tsai C.J., Yang J.T., Gillespie E.F. Stereotactic Body Radiation Therapy (SBRT) vs Stereotactic Ablative Radiation Therapy (SABR): Does Terminology Differentiate Treatment Intent in Metastatic Cancer? https://www.appliedradiology.org/courses/4549%2FPDF%2FARO_12-21_LapenCME.pdf (https://www.appliedradiology.org/courses/4549/PDF/ARO_12-21_LapenCME.pdf)
8 Loo BW Jr., Chang JY, Dawson LA, Stereotactic ablative radiotherapy: whaťs in a name? Pract Radiat Oncol. Jan-Mar 2011;1(1):38–9. doi:10.1016/j.prro.2010.07.001 24673868
9 Distiller SR. Evidence Partners Inc., Manotick, Ontario, Canada. Accessed Sept.-Dec. 2022, https://www.evidencepartners.com/.
10 Sterne JA C, Savovic J, Page MJ, RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ. Aug 28 2019;366:l4898. doi:10.1136/bmj.l4898
11 Schunemann H BJ, Guyatt G, Oxman A. GRADE Handbook. https://gdt.gradepro.org/app/handbook/handbook.html#:~:text=The%20GRADE%20hand book%20describes%20the,www.gradeworkinggroup.org).
12 GRADEpro GDT: GRADEpro Guideline Development Tool [Software]. McMaster University and Evidence Prime. Accessed Sept.-Dec. 2022,
13 Chang JY, Senan S, Paul MA, Stereotactic ablative radiotherapy versus lobectomy for operable stage I non-small-cell lung cancer: a pooled analysis of two randomised trials. The Lancet Oncology. 2015;16(6):630–7. Comment in: Lancet Oncol. 2015 Jun;16(6):597–8 PMID: 25981817 [https://www.ncbi.nlm.nih.gov/pubmed/25981817] Comment in: Lancet Oncol. 2015 Aug;16(8):e370–1 PMID: 26248836 [https://www.ncbi.nlm.nih.gov/pubmed/26248836] Comment in: Lancet Oncol. 2015 Aug;16(8):e371–2 PMID: 26248837 [https://www.ncbi.nlm.nih.gov/pubmed/26248837] Comment in: Lancet Oncol. 2015 Aug;16(8):e372–3 PMID: 26248838 [https://www.ncbi.nlm.nih.gov/pubmed/26248838] Comment in: Lancet Oncol. 2015 Aug;16(8):e372 PMID: 26248839 [https://www.ncbi.nlm.nih.gov/pubmed/26248839] Comment in: Lancet Oncol. 2015 Aug;16(8):e373–4 PMID: 26248840 [https://www.ncbi.nlm.nih.gov/pubmed/26248840] Comment in: Lancet Oncol. 2015 Aug;16(8):e374–5 PMID: 26248841 [https://www.ncbi.nlm.nih.gov/pubmed/26248841] Comment in: J Thorac Cardiovasc Surg. 2015 Sep;150(3):468–71 PMID: 26259993 [https://www.ncbi.nlm.nih.gov/pubmed/26259993] Comment in: Lancet Oncol. 2015 Sep;16(9):e422 PMID: 26370343 [https://www.ncbi.nlm.nih.gov/pubmed/26370343] Erratum in: Lancet Oncol. 2015 Sep;16(9):e427 PMID: 26370351 [https://www.ncbi.nlm.nih.gov/pubmed/26370351] Comment in: Strahlenther Onkol. 2015 Dec;191(12):988–90 PMID: 26459463 [https://www.ncbi.nlm.nih.gov/pubmed/26459463] Comment in: Lancet Oncol. 2016 Feb;17(2):e41–2 PMID: 26868347 [https://www.ncbi.nlm.nih.gov/pubmed/26868347] Comment in: Lancet Oncol. 2016 Feb;17(2):e42–3 PMID: 26868349 [https://www.ncbi.nlm.nih.gov/pubmed/26868349]. doi:10.1016/S1470-2045(15)70168-3 25981812
14 Louie AV, van Werkhoven E, Chen H, Patient reported outcomes following stereotactic ablative radiotherapy or surgery for stage IA non-small-cell lung cancer: Results from the ROSEL multicenter randomized trial. Radiotherapy and oncology: journal of the European Society for Therapeutic Radiology and Oncology. 2015;117(1):44–8. Comment in: Int J Radiat Oncol Biol Phys. 2016 Dec 1;96(5):927–930 PMID: 27869093 [https://www.ncbi.nlm.nih.gov/pubmed/27869093]. doi:10.1016/j.radonc.2015.08.011 26492839
15 Alexander ES, Dupuy DE, Machan JT, Ng T, Breen L, DiPetrillo T. Cost and effectiveness of radiofrequency ablation versus surgery for Stage I non-small cell lung cancer in the elderly: Is less more? Journal of Vascular and Interventional Radiology. 2011;22(3 SUPPL. 1):S54. 36th Annual Scientific Meeting of the Society of Interventional Radiology, SIR 2011 - IR Rising: Leading Image-Guided Medicine. Chicago, IL United States. Sponsor: Navylist Medical. (var.pagings). doi:10.1016/j.jvir.2011.01.136
16 Ambrogi MC, Fanucchi O, Dini P, Wedge resection and radiofrequency ablation for stage I nonsmall cell lung cancer. European Respiratory Journal. 2015;45(4):1089–1097. doi:10.1183/09031936.00188014 25700387
17 Hsie M, Morbidini-Gaffney S, Kohman LJ, Dexter E, Scalzetti EM, Bogart JA. Definitive treatment of poor-risk patients with stage i lung cancer: A single institution experience. Journal of Thoracic Oncology. 2009;4(1):69–73. doi:10.1097/JTO.0b013e3181914d3a 19096309
18 Hu H, Zhai B, Liu R, Chi J. Microwave Ablation Versus Wedge Resection for Stage I Non-small Cell Lung Cancer Adjacent to the Pericardium: Propensity Score Analyses of Long-term Outcomes. CardioVascular and Interventional Radiology. 2021;44(2):237–246. doi:10.1007/s00270-020-02601-7
19 Iguchi T, Hiraki T, Matsui Y, Survival Outcomes of Treatment with Radiofrequency Ablation, Stereotactic Body Radiotherapy, or Sublobar Resection for Patients with Clinical Stage I Non-Small-Cell Lung Cancer: A Single-Center Evaluation. Journal of Vascular and Interventional Radiology. 2020;31(7):1044–1051. doi:10.1016/j.jvir.2019.11.035 32471699
20 Kim SR, Han HJ, Park SJ, Comparison between surgery and radiofrequency ablation for stage I non-small cell lung cancer. European journal of radiology. 2012;81(2):395–9. doi:10.1016/j.ejrad.2010.12.091 21310562
21 Mendogni P, Daffre E, Rosso L, Percutaneous lung microwave ablation versus lung resection in high-risk patients. A monocentric experience. Acta bio-medica: Atenei Parmensis. 2020;91(10S):e2020002. doi:10.23750/abm.v91i10-S.10342
22 Safi S, Rauch G, Op Den Winkel J, Sublobar Resection, Radiofrequency Ablation or Radiotherapy in Stage i Non-Small Cell Lung Cancer. Respiration. 2015;89(6):550–557. doi:10.1159/000381555 25968471
23 Wang Y, Liu B, Cao P, Comparison between computed tomography-guided percutaneous microwave ablation and thoracoscopic lobectomy for stage I non-small cell lung cancer. Thoracic Cancer. 2018;9(11):1376–1382. doi:10.1111/1759-7714.12842 30152596
24 Zemlyak A, Moore WH, Bilfinger TV. Comparison of Survival after Sublobar Resections and Ablative Therapies for Stage I Non-Small Cell Lung Cancer. Journal of the American College of Surgeons. 2010;211(1):68–72. doi:10.1016/j.jamcollsurg.2010.03.020 20610251
25 Ochiai S, Yamakado K, Kodama H, Comparison of therapeutic results from radiofrequency ablation and stereotactic body radiotherapy in solitary lung tumors measuring 5 cm or smaller. International Journal of Clinical Oncology. 2015;20(3):499–507. doi:10.1007/s10147-014-0741-z 25130494
26 Yao W, Lu M, Fan W, Comparison between microwave ablation and lobectomy for stage I non-small cell lung cancer: a propensity score analysis. International Journal of Hyperthermia. 2018;34(8):1329–1336. doi:10.1080/02656736.2018.1434901 29378462
27 Ager BJ, Scheick S, Gruhl JD, Tao R, Kokeny KE, Hitchcock YJ. Stereotactic Body Radiotherapy versus Local Tumor Ablation for Early-Stage Non-Small Cell Lung Cancer. International Journal of Radiation Oncology Biology Physics. 2019;104(1):233–234. 2019 Thoracic Cancers Symposium. San Diego United States. doi:10.1016/j.ijrobp.2019.01.020
28 Baine MJ, Sleightholm R, Neilsen BK, Stereotactic Body Radiation Therapy Versus Nonradiotherapeutic Ablative Procedures (Laser/Cryoablation and Electrocautery) for Early-Stage Non-Small Cell Lung Cancer. Journal of the National Comprehensive Cancer Network: JNCCN. 2019;17(5):450–458. doi:10.6004/jnccn.2018.7269 31085762
29 Kwan SW, Mortell KE, Talenfeld AD, Brunner MC. Thermal ablation matches sublobar resection outcomes in older patients with early-stage non-small cell lung cancer. J Vasc Interv Radiol. Jan 2014;25(1):1–9 e1. doi:10.1016/j.jvir.2013.10.018 24365502
30 Lam A, Yoshida EJ, Bui K, Fernando D, Nelson K, Abi-Jaoudeh N. A National Cancer Database Analysis of Radiofrequency Ablation versus Stereotactic Body Radiotherapy in Early-Stage Non-Small Cell Lung Cancer. Journal of Vascular and Interventional Radiology. 2018;29(9):1211–1217.e1. doi:10.1016/j.jvir.2018.04.029 30061058
31 Li M, Xu X, Qin Y, Radiofrequency ablation vs. stereotactic body radiotherapy for stage IA non-small cell lung cancer in nonsurgical patients. Journal of Cancer. 2021;12(10):3057–3066. doi:10.7150/jca.51413 33854605
32 Uhlig J, Ludwig JM, Goldberg SB, Chiang A, Blasberg JD, Kim HS. Survival Rates after Thermal Ablation versus Stereotactic Radiation Therapy for Stage 1 Non-Small Cell Lung Cancer: A National Cancer Database Study. Radiology. 2018;289(3):862–870. Comment in: Radiology. 2018 Dec;289(3):871–872 PMID: 30226452 [https://www.ncbi.nlm.nih.gov/pubmed/30226452] Comment in: Radiology. 2019 Feb;290(2):574–575 PMID: 30599098 [https://www.ncbi.nlm.nih.gov/pubmed/30599098]. doi:10.1148/radiol.2018180979 30226453
33 Deng HY, Wang YC, Ni PZ, Radiotherapy, lobectomy or sublobar resection? A meta-analysis of the choices for treating stage I non-small-cell lung cancer. Eur J Cardiothorac Surg. Feb 1 2017;51(2):203–210. doi:10.1093/ejcts/ezw272 28186277
34 Joseph KS, Mehrabadi A. & Lisonkova S. Confounding by Indication and Related Concepts. Curr Epidemiol Rep. 2014;1(March 2014):1–8. doi:10.1007/s40471-013-0004-y
35 Chang JY, Mehran RJ, Feng L, Stereotactic ablative radiotherapy for operable stage I non-small-cell lung cancer (revised STARS): long-term results of a single-arm, prospective trial with prespecified comparison to surgery. Lancet Oncol. Oct 2021;22(10):1448–1457. doi:10.1016/S1470-2045(21)00401-0 34529930
36 Jiang B, McClure MA, Chen T, Chen S. Efficacy and safety of thermal ablation of lung malignancies: A Network meta-analysis. Ann Thorac Med. Oct-Dec 2018;13(4):243–250. doi:10.4103/atm.ATM_392_17
37 Franks KN, McParland L, Webster J, SABRTooth: a randomised controlled feasibility study of stereotactic ablative radiotherapy (SABR) with surgery in patients with peripheral stage I nonsmall cell lung cancer considered to be at higher risk of complications from surgical resection. Eur Respir J. Nov 2020;56(5)doi:10.1183/13993003.00118-2020