# ACKNOWLEDGMENTS

The authors are grateful to the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Drew Moghanaki, MD, MPH
  Staff Physician
  Co-Director Lung Precision Oncology Program
  VA Greater Los Angeles Healthcare System

## Technical Expert Panel

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Jed Gorden, MD
  Pulmonary Critical Care, Thoracic Surgery, Thoracic Surgical Oncology
  Swedish Medical Group, Seattle
- Lorraine Cornwell, MD, FACS
  Section Chief of Cardiothoracic Surgery
  Michael E. DeBakey VA Medical Center, Houston
- Russell Hales, MD
  Department of Radiation Oncology & Molecular Radiation Sciences
  Johns Hopkins University
- Christopher Slatore, MD, MS
  Chief Consultant, VHA National Center for Lung Cancer Screening
  Director, VISN 20 Centralized Lung Cancer Screening Program
  Portland VA Healthcare System
- Robert Suh, MD
  Interventional Radiology, Diagnostic Radiology
  UCLA

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence (see Appendix D for disposition of comments). Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center works to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.