# DISCUSSION

## KEY MESSAGES

### Key Question 1 and 2

- Based on pooled data from the STARS and ROSEL trials comparing SABR/SBRT versus surgery, the evidence for 3-year survival, 3-year recurrence-free survival, quality of life, and adverse events is very uncertain (very low certainty of evidence).
  - Only 2 randomized trials, STARS and ROSEL, were identified that evaluated the role of SABR/SBRT compared to surgery for patients with medically operable stage I non-small cell lung cancer; both were terminated early due to lack of enrollment.
- No randomized trials were identified that examined if the benefits and harms of SABR/SBRT differ by patient characteristics, tumor characteristics, surgery characteristics, type of resection, or SBRT characteristics.
- There is an urgent need for randomized controlled trials to examine the comparative effectiveness of SABR/SBRT versus surgery for patients with medically operable stage I lung cancer.

We found insufficient evidence to inform the comparative effectiveness of SBRT/SABR versus surgery for stage I medically operable lung cancer. Our conclusions are based on 1 publication that pooled data from the STARS and ROSEL trials, which analyzed 58 persons with medically operable lung cancer (31 in the SABR group and 27 in the surgery group).^13^ Both trials were terminated early due to low accrual rates over a 5-year time period (2008–2013). One additional study of 22 individuals randomly assigned to SABR (N = 11) and surgery (N = 11) over a median follow-up of 42 months evaluated quality of life using the EORTC QLQ-C30, 13-item lung cancer supplement (LC-13), and EQ-5D, which were administered at baseline, 3, 6, 12, 18, and 24 months.^14^

Based on these 2 studies, we have very low certainty in the comparative effectiveness of SABR versus surgery for the following outcomes: 3-year overall survival, 3-year recurrence-free survival, adverse events, and quality of life. Of the 27 patients who received surgery, 19 had open lobectomies, 5 had video-assisted thoracotomy lobectomies, 1 had video-assisted thoracotomy biopsy (mediastinal lymph node biopsy positive for metastatic lung cancer), 1 had open wedge resection (benign lung nodule), and 1 had an aborted resection during the surgery due to disease progression. Our very low certainty in the pooled estimates is based on concerns of performance and detection bias across the 2 trials, very small number of events in the 2 intervention groups (only 7 total deaths over 3 years), and low rates of minimally invasive surgical resection in the surgery arm (indirectness). Therefore, there is insufficient evidence (very low certainty) of the effects of SABR versus surgery.

While the evidence base was very sparse and deemed insufficient to address the comparative effectiveness of SBRT versus surgery, we found no data evaluating KQ2: ie, whether benefits and harms of SBRT compared with surgery differed by patient, tumor characteristics, surgery, or SBRT characteristics. These characteristics are important as clinical decisions often include these factors, and variation in these characteristics may confound findings from observational studies.

Randomized trials, including the ongoing VA Cooperative Studies Program VALOR trial,^6^ are unlikely to be of sufficient size and design to adequately address all of these potential effect modifiers. However, researchers should include these components in future study designs and analyses.

These findings must be interpreted in the context of a large body of observational studies that have tried to address this question.^33^ An important limitation of observational studies is that selection bias or confounding by indication may lead to inaccurate estimations of treatment effects. Confounding by indication is defined as a bias in the treatment-related outcome relationship due to the clinical reasons for the treatment. The indication for the treatment is based on physician and patient perceptions of disease severity and prognosis, including the presumed therapeutic effect of the intervention.^34^ One approach to attempt to reduce this bias is the use of propensity-matched comparisons.

In the absence of evidence from randomized trials, investigators conducted a follow-up study of the STARS trial that used propensity matching.^35^ This study was excluded during the full-text review process since it did not meet our required study design criteria for a RCT. In this single-center prospective observational study, the SABR group was re-accrued (using a revised STARS protocol) to allow for a larger sample size. Participants were then compared to a cohort of individuals that underwent video-assisted thorascopic surgical lobectomy with mediastinal lymph node dissection (VATS L-MLND) using a protocol-specified propensity-matched comparison. Propensity matching was performed for the following covariates: age, tumor, histology, performance status, and the interaction of age and sex. The following outcomes were reported: overall survival at 3 and 5 years, progression-free survival, cancer-specific survival rates, patterns of failure, predictive value of PET scans, local recurrence-free survival, and incidence of grade 3 or worse toxicity. Overall, 10 deaths occurred, and 15 patients developed progression in the SABR group over a median follow up of 5.1 years. In the surgery group, there were 15 deaths and 6 recurrences or distant metastases. The authors reported that overall survival at 3 years in the SABR group was 91% (95% CI [85%, 98%]) compared with 91% (95% CI [76%, 98%]) in the propensity-matched VATS-LMND cohort. Furthermore, overall survival at 5 years in the SABR cohort was 87% (95% CI [79%, 95%]) compared with 84% (95% CI [76%, 93%]) in the surgery cohort. Based on these results, SABR was reported to be non-inferior to VATS-MLND for operable stage IA NSCLC.

The authors acknowledged that propensity score matching was performed only for known potential variables. Thus, there may still be bias due to residual confounding from unknown variables for which matching was not performed. Additional limitations as outlined by the authors included persistent concerns about selection bias of patients enrolled into the revised STARS study due to lack of randomization, and concerns about determination of medical operability since the surgical cohort was not treated under a fixed protocol. Notwithstanding the results showing similar outcomes for these 2 interventions suggesting that SBRT/SABR is equally effective as compared to surgery (specifically VATS L-MLND), there is an urgent need for randomized controlled trials examining the comparative effectiveness of these 2 treatment modalities to inform practitioners and patients of the optimal treatment for stage I medically operable lung cancer.

### Key Question 3

- There are no RCTs of ablation therapies for stage I lung cancer. The following ablation therapies have been studied in non-randomized comparative studies: cryoablation, radiofrequency ablation, microwave ablation, and laser ablation. Radiofrequency ablation was the most commonly studied ablative therapy (k = 11).
- Six retrospective studies reported on ablation compared with SBRT/SABR:
  ○ Ablation (any type combined) versus SBRT/SABR (k = 3)
  ○ Radiofrequency ablation versus SBRT/SABR (k = 3)
- Ten retrospective studies reported on ablation compared with surgery:
  ○ Microwave ablation versus surgery (k = 4)
  ○ Radiofrequency ablation versus surgery (k = 4)
  ○ Ablation (any type combined) versus surgery (k = 2)
  ○ SBRT/SABR versus radiofrequency ablation versus surgery (k = 2)
- Two studies compared ablation with SBRT/SABR and surgery:
  ○ SBRT/SABR versus radiofrequency ablation versus surgery (k = 2)
- Most studies had 300 or fewer participants (k = 12) and were conducted in the US (k = 9), Europe (k = 3), China (k = 3), Japan (k = 2), and South Korea (k = 1), with the exception of 6 studies of administrative datasets (NCDB and SEER) and included 2,000–30,000 participants.
- The majority of studies reported on the following outcomes: overall survival (k = 18), disease-free survival (k = 8), local/regional recurrence (k = 12), and any adverse events (k = 11). No studies reported on quality of life.
- None of these studies were conducted in Veterans and most studies were conducted prior to widespread lung cancer screening.

Ablative therapies using thermal ablation (radiofrequency ablation, microwave ablation, and laser ablation), cryoablation, and brachytherapy are often used as modalities for palliative treatment or in individuals with inoperable cancers, but these therapies have increasingly been used in medically operable individuals with lung cancer.^36^ Based on our evidence map, there were a limited number of comparative studies of ablative treatments versus surgery for lung cancer. Most of these studies did not specify medically operable patients and did not provide the stage of disease. Furthermore, studies commonly reported on ablation versus surgery or SBRT/SABR without providing data on specific ablative therapies and stratifying results by ablative technique. When individual studies of ablation were reported, the most common ablative therapy was radiofrequency ablation.

The majority of studies reported on overall and lung-cancer-specific survival as well as disease recurrence and treatment-related adverse events. For adverse events, most studies reported short-term respiratory complications (k = 10) or short-term cardiovascular complications (k = 5). Only 1 study reported long-term respiratory complications and 2 reported on hospital readmissions.

However, reporting of short-term versus long-term AEs was not well defined, and it was difficult to tell from the articles if there was a follow-up period in which adverse events were being recorded. There were no studies reporting on quality of life. Most studies did not specify medically operable patients and did not provide the stage of disease. Due to the heterogeneity of the studies with respect to patient populations (combing medically operable with non-medically operable patients), interventions (data not provided for specific ablative therapy), and study designs, we did not pool across studies and make inferences about effect size or overall certainty of evidence. Since several studies were using administrative datasets, there was also concern about “double counting.”

This evidence map for ablative therapies provides an overview of the scientific evidence, gaps in current knowledge, and needs of future research using visual analysis and graphic illustrations to help facilitate interpretation of results. This provides valuable information to researchers and funding organizations, as future clinical trials of different ablative therapies in individuals with medically operable lung cancer are needed to help inform practitioners and patients about the optimal role for ablative therapies within the framework of more established therapies such as surgery and SBRT.

## LIMITATIONS

We acknowledge the following limitations of this evidence review. The results for the pooled analysis of the trials comparing SABR versus surgery were obtained from a publication of a post-hoc analysis of the 2 trials that had been terminated early due to lack of enrollment. We did not independently extract or pool the results from the trials, as the primary data were provided from the principal investigator for only 1 of the 2 trials despite attempts to obtain the results for each study. Furthermore, we focused our comparative effectiveness review on randomized controlled trials, in discussion with our nominating partner and TEP members. While numerous observational studies exist, including studies that utilize propensity matching, such study designs have not adequately addressed questions about comparative effectiveness and harms.

For the evidence map, we included observational studies with a comparator arm to better understand how ablative therapies have been evaluated as compared to standard therapies. Some of the retrospective studies of administrative datasets may have had overlapping years for patient selection and individuals may have been “double counted” across studies. Furthermore, these studies did not clearly distinguish medically operable versus inoperable persons and provided limited reporting on how individuals were selected to receive specific treatments. In this evidence map, we also did not provide information on effect size, direction of effect, or assessment of quality of studies to limit misinterpretation or over reliance on these studies for decision-making. These limitations notwithstanding, the evidence map outlines the current landscape of studies that have compared various ablative treatment strategies to inform the research agenda for future clinical trials.

## APPLICABILITY

None of the studies were specific to VA populations. The ongoing VALOR RCT,^6^ funded by the VA Cooperative Studies Program (CSP #2005) aims to recruit 670 Veterans from at least 16 VA hospitals to compare stereotactic radiotherapy to standard lobectomy or segmentectomy for the treatment of medically operable, histologically confirmed, centrally or peripherally located stage I non-small cell lung cancers. Importantly, adequate recruitment and follow-up will be critical to the success of this trial. Establishing equipoise and addressing patient treatment preferences will be an important barrier to overcome.^37^ As management of lung cancer patients requires extensive multidisciplinary care and follow-up, interventions that support “buy-in” from different subspecialists and opportunities for shared decision-making as well as sustained efforts to promote recruitment into the trial will also be critical.

## FUTURE RESEARCH

The results of our systematic review underscore the recognition that data from randomized controlled trials, especially that of the VA Cooperative Study VALOR,^6^ are critically needed to inform decisions around primary treatment for stage I lung cancer. The scarcity of randomized trial data is a major limitation in understanding the comparative effectiveness of different treatment strategies. This is particularly relevant given that the updated recommendations for expanded lung cancer screening incorporate surgical candidacy or willingness to undergo surgery as a prerequisite for offering screening.

Future studies should:

- Use consistent terminology or definitions for medically operable disease using standardized protocols for enrollment to further minimize selection bias or confounding by indication and provider bias for enrollment.
- Ensure adequate experience and training in the performance of minimally invasive surgery and ablative therapies.
- Ensure adequate enrollment and follow-up to have adequate sample size to detect clinically meaningful differences in overall and cancer-specific survival, tumor-free progression, adverse effects, quality of life, and long-term side effects (using consistent definitions).
- Be pragmatic in design to ensure that studies address the range of patients, tumors, and interventions under clinical consideration for individuals with newly diagnosed lung cancer (especially screen detected).
- Recruit patient engagement groups to understand barriers and seek solutions to randomization in trials of these vastly different treatments, and examine values and preferences, acceptability, and feasibility.
- Assess potential expansion of treatment options for stage I lung cancer to include SABR/SBRT and/or ablative therapies (potentially as a 3-arm trial).
- Explore how inclusion of screen-detected lesions would influence screening and treatment decisions and resultant net benefits. This includes use of less invasive therapies for small, indolent lung cancers among older sicker adults who would otherwise not have been candidates for screening or subsequent treatment.

## CONCLUSIONS

In summary, the evidence is uncertain on the comparative effectiveness and harms of surgery versus SBRT/SABR for adults with medically operable lung cancer. Lung cancer is among the most common and lethal cancers globally. Those with early stage, especially cancers detected by low-dose CT screening, have the highest chance for effective therapies and mortality reduction. While surgery has been commonly considered the treatment strategy of choice for medically operable disease, stereotactic radiotherapy has emerged as an alternative treatment strategy. Given current evidence uncertainty, overall disease burden, and the growing role of lung cancer screening, robust randomized controlled trial results are needed. Furthermore, the field of ablative therapies continues to innovate and expand and is becoming more widely studied. There is a critical need for robust evidence on comparative treatment effects as well as patient preferences and values to inform the management of patients with medically operable stage I non-small cell lung cancer.