# RESULTS

## KEY QUESTIONS 1 AND 2

KQ1 Among adults with medically operable stage I non-small cell lung cancer, what are the benefits and harms of stereotactic beam radiotherapy (SBRT) compared to surgery?
KQ2 Do benefits and harms of SBRT/SABR compared to surgery differ by patient characteristics (eg, age, comorbidities, performance status), tumor characteristics (size, location, stage), surgery characteristics (type of surgery [minimally invasive vs open], type of resection [lobectomy, wedge resection, segmental resection, sleeve resection]), or SBRT characteristics (eg, dose, fractionation)?

### Literature Flow

The literature flow diagram (Figure 1) summarizes the results of the study selection process. The full list of excluded studies is available in Appendix B.

### Literature Overview

Our search identified 2,959 potentially relevant citations. After title and abstract screening, 27 were moved forward to full-text review. Of those 27, we identified only 2 publications which met inclusion criteria for KQ1. Studies were excluded for the following reasons: ineligible publication type or study design (eg, commentaries or non-randomized studies), ineligible intervention or outcome (eg, radiotherapy vs chemotherapy or chemoradiation), and ineligible outcome (eg, treatment preferences). No eligible publications were identified that addressed KQ2.

One publication, Chang et al,^13^ pooled data from 2 randomized trials: the Randomized Study to Compare CyberKnife to Surgical Resection In Stage I Non-Small Cell Lung Cancer (STARS) trial and the Trial of Either Surgery or Stereotactic Radiotherapy for Early Stage (IA) Lung Cancer (ROSEL) trial. Both trials had similar inclusion criteria (Table 2) and both were terminated early due to low recruitment. Both trials reported overall survival at 1 and 3 years, 3-year recurrence-free survival, and adverse events. The clinical trials had similar enrollment criteria with minor differences: histological confirmation was not required for the ROSEL trial as compared to the STARS trial, and follow-up intervals in the STARS trial were longer. Table 3 describes the STARS and ROSEL trial population characteristics and results individually, as well as the pooled results as reported in the Chang et al^13^ article. Data from the STARS trial were obtained from Clinicaltrials.gov, and data from the ROSEL trial were provided by trial investigators. The second publication, Louie et al,^14^ reported quality of life data from the ROSEL trial. Both publications were judged to have “some concerns” for risk of bias.

Figure 1 KQs 1 and 2 Literature Flowchart

Table 2 Overview of STARS (Randomized Study to Compare CyberKnife to Surgical Resection in Stage I Non-small Cell Lung Cancer) and ROSEL (Trial of Either Surgery or Stereotactic Radiotherapy for Early Stage (IA) Lung Cancer) Clincial Trial Information

Characteristics | STARS | ROSEL
Trial # | NCT00840749 (https://clinicaltrials.gov/ct2/show/NCT00840749) | NCT00687986 (https://clinicaltrials.gov/ct2/show/NCT00687986)
Country | 28 sites in USA, China, and France (7 sites enrolled participants) | 10 sites in Netherlands (4 sites enrolled participants)
Funding | Accuray (Industry) | Netherlands Organization for Health Research and Development
Inclusion criteria | - Patients with a histological confirmation of non-small cell cancer required by either biopsy or cytology. The following primary cancer types were eligible: squamous cell carcinoma, adenocarcinoma with or without BAC features, large cell carcinoma with or without neuroendocrine features, neuroendocrine carcinoma, bronchioloalveolar cell carcinoma, or non-small cell carcinoma not otherwise specified.; - Patients had to have appropriate staging studies identifying them as specific subsets of the revised IASCL state IA or IB based on only 1 of the following combinations of TNM staging: T1, N0, M0 or T2 (≤4 cm), N0, M0.; - Mandatory staging studies were done within 8 weeks prior to study entry. A PET/CT scan was required.; - Patients with hilar or mediastinal lymph nodes with short axis diameter <1 cm and no abnormal hilar or mediastinal uptake on PET were considered N0. Patients with >1 cm short axis diameter of hilar or mediastinal lymph nodes on CT or abnormal PET (including suspicious but non-diagnostic uptake) were still eligible if directed tissue biopsy of all abnormally identified areas were negative for cancer. Solitary pulmonary lesions <4 mm were not considered significant.; - Patients had to be considered reasonable candidates for surgical resection of the primary tumor. Standard justification for deeming a patient medically operable based on pulmonary function for surgical resection of NSCLC included any of the following: baseline FEV1 >40% predicted, post-operative predicted FEV1 >30% diffusion capacity >40% predicted, absent baseline hypoxemia and/or hypercapnia, exercise oxygen consumption >50% predicted, absent severe pulmonary hypertension, absent severe cerebral, cardiac, or peripheral vascular disease, and absent severe chronic heart disease.; - Patients had to be ≥18 years of age; - Patient’s Zubrod performance status had to be Zubrod 0-2 | - Patients with a cytological or histological diagnosis of stage IA non-cell lung cancer diagnosed in accordance with Dutch CBO guidelines. When no pathological diagnosis was available, a patient with a new or growing pulmonary lesion with radiological features consistent with malignancy AND a lesion showing uptake on a FDG-PET scan were eligible.; - No evidence of regional or distant metastases on a standardized FDG-PET scan within 6 weeks of any protocol treatment; - The medial extension of tumors at least 2 cm away from main and lobar bronchi, and also minimum of 1.5 cm from large peripheral blood vessels such as the aorta and main pulmonary artery. Lesions of at least 2 cm from the mediastinal pleura eligible if the responsible radiation oncologist judged that the specified normal tissue tolerance doses specified in the protocol were not to be exceeded.; - Patients who were judged by a multi-disciplinary team to have 2 primary lung tumors (on the basis of clinical, radiological, FDG-PET and/or cyto-pathology findings) were eligible for randomization provided that both surgery and SRT could be performed in accordance with protocol requirements.; - Patient had to be fit to undergo a complete surgical resection of the lesion in accordance with 2004 Dutch CBO guidelines.; - Performance score of ECOG ≤2 was required before any treatment.
Exclusion criteria | - Patients with primary tumors >4 cm; - Patients with well-differentiated neuroendocrine carcinoma (carcinoid tumor); - Patients in whom acceptable SRT planning to meet minimal requirement of target coverage and dose-volume constraints of critical structures were not achievable; - Evidence of regional or distant metastases, or synchronous primary or prior malignancy in the past 5 years other than non-melanomatous skin cancer or in situ cancer; - Prior lung or mediastinal radiotherapy; - Plans for concomitant local therapy (including standard fractionated radiotherapy and surgery) while on this protocol except at disease progression; - Pregnant or lactating women (as treatment involved unforeseeable risks to the embryo or fetus) | - Patients with any unstable systemic disease (including active infection, uncontrolled hypertension, unstable angina, congestive heart failure, myocardial infarction within the previous year, severe cardiac arrhythmia requiring medication, hepatic, renal or metabolic disease).; - Prior or active malignancy (other than NSCLC) unless treated more than 3 years prior with curative intent and no recurrence, with the exception of non-melanoma skin cancers or in-situ cervical cancers; - Prior chemotherapy or radiotherapy for the present diagnosis of NSCLC; - Plans for concomitant treatment with any other experimental drug under investigation; - Pregnancy; - Men and women of child-bearing potential who were not using effective means of contraception for 6 months after treatment
Radiotherapy characteristics | CyberKnife system (Accuray, Sunnyvale, CA, USA) was used for all radiotherapy sessions. Patients with peripherally located lesions (ie, those located >2 cm in any direction from the proximal bronchial tree, major vessels, oesophagus, heart, tracheal, vertebral body, pericardium, mediastinal pleural, and brachial plexus) received a total radiation dose of 54 Gy in three 18 Gy fractions (BED 151.2 Gy), calculated with a Monte Carlo or equivalent algorithms or its equivalent dose if other algorithms were used and heterogeneity correction. For central lesions (ie, those within 2 cm of these structures), 50 Gy in 4 12.5 Gy fractions (BED 112.5 Gy) was used. The SABR dose was prescribed to the highest isodose line, which was required to cover 100% of the gross tumor volume (defined as visible disease in CT images with use of lung window) and more than 95% of the planning target volume (defined as the gross tumor volume plus a 3 mm margin). Coverage of 100% of the planning target volume by at least the prescription dose was encouraged. The normal tissue constraints were met for all cases. Treatment delivery was recommended to be complete within 5 days of its initiation. | Linear-accelerator-based SABR from multiple vendors was used. Only lesions located 2 cm or more from the hilar structures on the diagnostic CT scan were eligible. A toxicity risk-adapted fractional scheme was used in which a total dose of 54 Gy in 3 18 Gy fractions (BED 151.3 Gy), calculated with a Monte Carlo or equivalent algorithms or its equivalent doses if other algorithms were used and heterogeneity correction, and given over 5–8 days; alternatively, a total dose of 60 Gy at 5 12 Gy fractions (BED 132.0 Gy), was given over 10–14 days (to account for different treatment-delivery practices in Dutch centers). The SABR dose prescription was chosen such that 95% of the planning target volume, the internal target volume (based on four-dimensional CT), or other equivalent approaches to take tumor motion into consideration—plus a 3–5 mm margin for setup and motion uncertainty—would receive at least the nominal fraction dose, and 99% of the planning target volume would receive at least 90% of the fraction dose. The preferred maximum dose within the planning target volume was between 110% and 140% of the prescribed dose.
Surgery characteristics | Both open thoracotomy and video-assisted thoracotomy (VATS) were acceptable procedures. Surgery could consist of a lobectomy, sleeve resection, bi-lobectomy, or pneumonectomy as determined by the attending surgeon based on the operative findings. | Any anatomical surgical resection with lymph node dissection

Abbreviations. BAC=bronchoalveolar carcinoma; BED=biologically effective dose; CBO=Centraal Begeleidingsorgaan voor de Intercollegiale Toetsing (Dutch Institute for Healthcare Improvement); CT=computed tomography; ECOG=Eastern Cooperative Oncology Group; FEV=forced expiratory volume; FDG-PET=fluorodeoxyglucose-positron emission tomography; IASCL=International Association for the Study of Lung Cancer; SABR=stereotactic ablative radiotherapy; TNM=tumor, node, metastasis; USA =United States of America.

### Overall Survival at 3 Years

Overall survival at 3 years, using pooled data from the STARS and ROSEL trials on 58 patients, was reported in 1 publication.^13^ When compared to surgery, the HR for 3-year overall survival was 0.14 (95% CI [0.017, 1.19]) based on follow-up of 35–40 months. However, both the radiotherapy and surgery arm had a very small number of deaths at 3 years, 1 in the SABR/SBRT arm and 5 in the surgery arm. Based on the limited number of individuals who underwent non-invasive surgery and based on both trials being terminated early, we are very uncertain about the effect of SABR/SBRT on overall survival at 3 years, as compared with surgery (very low certainty of evidence). A summary of findings is presented in Table 4.

### Recurrence-Free Survival

Recurrence-free survival at 3 years was reported in the same publication^13^ using pooled data from the STARS and ROSEL trials. When compared to surgery, over a follow up of 35–40 months, the HR was 0.69 (95% CI [0.21, 2.29]). However, as outlined above, the effect of SABR/SBRT on recurrence-free survival at 3 years compared to surgery is very uncertain (very low certainty of evidence).

### Adverse Events

The same publication reported on grade ≥3 adverse events, using pooled data on 58 patients from the STARS and ROSEL trials.^13^ When compared to surgery, the effect of SABR on grade ≥3 adverse events is very uncertain (Table 4). Specific adverse events as captured and reported by the individual trials are summarized in Table 3. Three grade ≥3 adverse events were reported across the 2 arms in the STARS cohort (N = 36). Sixteen grade ≥3 adverse events were reported across the 2 arms of the ROSEL cohort: 7 events in the SABR/SBRT arm (N = 11) and 9 events in the surgery arm (N = 11).

### Quality of Life

One publication addressed quality of life (QoL) in participants (N = 19) treated with SABR compared to surgery, using data from the ROSEL trial.^14^ In this study, the following tools (administered at baseline, 3, 6, 12, 18, and 24 months) were used to assess QoL: the 30-item European Organization for Research and Treatment of Cancer Quality of Life Core questionnaire (EORTC QLQ-C30, 13-item lung cancer supplement [LC-13] and the EuroQoL disease-specific questionnaire [EQ-5D]). Minimum thresholds of a 10-point decrease (for global and functional scales) and increase (for symptom scales and items) were used to denote a clinically meaningful difference. The following scales/items were reported: physical functioning, role functioning, emotional functioning, cognitive functioning, social functioning, global health status/QoL, fatigue, nausea/vomiting, pain, dyspnea, insomnia, appetite loss, constipation, diarrhea, financial problems, coughing, hemoptysis, sore mouth, dysphagia, peripheral neuropathy, alopecia, pain in chest, pain in arm or shoulder, pain in other parts, and dyspnea. If at any point in the study period the participant had a ≥10-point decrease from a prior rating, this was considered a meaningful event. In all comparisons, only global health status was found to be significantly worse on univariable Cox proportional hazard modeling for surgical patients when compared to SABR (HR = 0.19; 95% CI [0.04, 0.91]). However, this is based on a small number of patients with limited number of events and low rates of minimally invasive surgery (Table 5). Therefore, when compared to surgery, the effect of SABR on quality of life is very uncertain (very low certainty of evidence).

Table 3 Study Characteristics for All Eligible Trials Reporting Survival or Adverse Events

Characteristics & Outcomes | | STARS^*^ | | ROSEL^†^ | | Chang (Pooled STARS & ROSEL)
Characteristics & Outcomes | | SABR | Surgery | SABR | Surgery | SABR | Surgery
Baseline Characteristics
N (% female) | | 36 (50) | | 11 (27) | 11 (36) | 31 (55) | 27 (59)
Age | | 18-65: 16 (44); ≥65: 20 (56) | | Median (IQR): 65 (61-71) | Median (IQR): 65 (62-72) | Mean (SD): 67.3 (9.2) | Mean (SD): 67.3 (8.2)
Median follow-up (IQR) | | NR | | Median (IQR): 42 months (20-54) | | 40.2 months (23.0 to 47.3) | 35.4 months (18.9 to 40.7)
Tumor location N (%): | | NR | | Lower L: 5 (45); Upper L: 1 (9); Lower R: 2 (18); Middle R: 1 (9); Upper R: 2 (18) | Lower L: 2 (18); Upper L: 4 (36); Lower R: 0 (0); Middle R: 0 (0); Upper R: 5 (45) | Lower L: 7 (23); Upper L: 7 (23); Lower R: 5 (16); Middle R: 3 (10); Upper R: 9 (29) | Lower L: 4 (15); Upper L: 8 (30); Lower R: 1 (4); Middle R: 2 (7); Upper R: 12 (44)
Tumor stage: N (%) | | NR^ǂ^ | | NA = 11^ǀ^ | T0: 1 (9); T1: 9 (82); T2: 1 (9) | T1a: 16 (52); T1b: 11 (35); T2a: 4 (13) | T1a: 18 (67); T1b: 8 (30); T2a: 1 (4)
Type of radiotherapy or surgery | | 54 Gy/3; Fx: 16; 50 Gy/4; Fx: 4 | NR | 54 Gy in 3 18 Gy fractions over 5-8 days: 6; 60 Gy at 5 12 Gy fractions over 10-14 days: 5 | Lobectomy: 10; Wedge resection: 1 | -- | Open lobectomy: 19; VATL: 5; VATB: 1; Wedge resection: 1; Aborted resection: 1
Survival Outcomes
3-year overall survival (n/N) | | 31/36 | | 10/11 | 10/11 | 95% (85 to 100); 30/31 | 79% (64 to 97); 22/27
3-year overall survival (n/N) | | 31/36 | | 10/11 | 10/11 | HR = 0.14 (0.017 to 1.190), p = 0.037
3-year recurrence-free survival (n/N) | | NR | | 9/11 | 8/11 | 86% (74 to 100); 26/31 | 80% (65-97); 21/27
3-year recurrence-free survival (n/N) | | NR | | 9/11 | 8/11 | HR = 0.69 (0.21 to 2.290), p = 0.54
Adverse Events
Any treatment-related grade 2+ adverse events (n/N) | | 3/36 | | 7/11 | 9/11 | Grade 3+: 9.7% (−24 to 43)^‡^; 3/31 | Grade 3+: 48% (21 to 75) ^‡^; 13/27
Grade 2+ dyspnoea or cough (n/N) | | 0/36 | | 5/11 | 6/11 | Grade 3+: 6% (2/31) | Grade 3+: 19% (5/27)
SBRT toxicity | Grade 2+ pneumonitis (n/N) | 0/36 | | 0/11 | 0/11 | NR
SBRT toxicity | Grade 2+ esophagitis | NR | | NR | | NR
Short-term (≤30 days) | Respiratory complications (pneumonia, hemothorax, pneumothorax, air leak, oxygen dependence at discharge) | NR | | NR | | NR
Short-term (≤30 days) | Cardiovascular complications (MI/CVA/atrial fibrillation) | 0/36 | | 2/11 | 0/11 | NR
Short-term (≤30 days) | Hospital readmissions | NR | | NR | | NR
Long-term (>30 days) | Respiratory complications (cough, pneumonia, dyspnea, oxygen dependence) | NR | | NR | | NR
Long-term (>30 days) | Pain (requiring medical intervention) | NR | | NR | | NR

Notes.

* Data taken from results posted on clinicaltrials.gov; trial investigators were contacted.

† Data was provided by principal investigator of ROSEL trial.

‡ Calculated by review authors.

ǂ Authors used International Association for the Staging of Lung Cancer (IASLC) 8^th^ edition to stage participants.

ǀ Authors used American Joint Commission on Cancer (AJCC) 7^th^ edition to stage participants.

Abbreviations. CVA=cerebral vascular accident; Gy=Gray; HR=hazard ratio; IQR=interquartile range; L=left; MI=myocardial infarction; NA=not available; NR=not reported; R=right; ROSEL=Trial of Either Surgery or Stereotactic Radiotherapy for Early Stage (IA) Lung Cancer; SABR=stereotactic ablative radiotherapy; SD=standard deviation; STARS=Randomized Study to Compare CyberKnife to Surgical Resection in Stage I Non-small Cell Lung Cancer; VATB=video-assisted thoracotomy biopsy; VATL=video-assisted thoracotomy lobectomies.

Table 4 Certainty of Evidence for SABR/SBRT versus Surgery for Lung Cancer Outcomes

Outcome | Median Follow-up; No. of Participants; (Studies) | Relative Effect (95% CI) | Anticipated Absolute Effects (95% CI) | | Certainty | What Happens
Outcome | Median Follow-up; No. of Participants; (Studies) | Relative Effect (95% CI) | Risk with Surgery | Risk Difference with SBRT/SABR | Certainty | What Happens
3-year overall survival | 35-40 months; N = 58; (2 RCTs) | HR = 0.14; (0.017, 1.19) | 815 per 1,000 | 157 more survived per 1,000 (31 fewer to 182 more) | ⨁◯◯◯; Very Low^a,b,c^ | The evidence is very uncertain about the effect of SABR/SBRT on overall survival.
3-year recurrence-free survival | 35-40 months; N = 58; (2 RCTs) | HR = 0.69; (0.21, 2.29) | 778 per 1,000 | 63 more survived per 1,000 (215 fewer to 171 more) | ⨁◯◯◯; Very Low^a,b,c^ | The evidence is very uncertain about the effect of SABR/SBRT on recurrence-free survival.
Grade ≥3 adverse events | 35-40 months; N = 58; (2 RCTs) | RR = 0.27 ^†^; (0.08, 0.87) | 481 per 1,000 | 351 fewer had a Grade ≥3 adverse event per 1,000 (443 fewer to 63 fewer) | ⨁◯◯◯; Very Low^a,b,c^ | The evidence is very uncertain about the effect of SABR/SBRT on grade ≥3 adverse events.
Reduction in quality of life | 42 months; N = 22; (1 RCT) | RR = 0.41 ^†^; (0.11, 1.59) | 800 per 1,000 | 472 fewer had a reduction in quality of life per 1,000 (712 fewer to 472 more) | ⨁◯◯◯; Very Low^a,b,c^ | The evidence is very uncertain about the effect of SABR/SBRT on quality of life.

Notes. The risk in the intervention group (and its 95% confidence interval) is based on the assumed risk in the comparison group and the relative effect of the intervention (and its 95% CI).

† Calculated by review authors.

High certainty: we are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: we are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: we have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations

a Downgraded for study limitations (lack of blinding of participants, investigators, and outcome adjudicators). Both studies terminated early due to issues with enrollment.

b Downgraded 2 levels for imprecision due to very small number of events.

c Downgraded for indirectness. The surgery group had low rates of minimally invasive surgical resection (eg, VATS).

Table 5 Study Characteristics for All Eligible Publications Reporting Quality of Life

Author, Year; Risk of Bias Trial(s) | Characteristics & Outcomes | Surgery | SABR | Results
Louie, 2015^14^; Some concerns; ROSEL | N (% female) | 11 (27) | 11 (36) | -
Louie, 2015^14^; Some concerns; ROSEL | Median age (range) | 65 (59-74) | 65 (52-75) | -
Louie, 2015^14^; Some concerns; ROSEL | Median follow-up (range) | 42 months (6-61) | | -
Louie, 2015^14^; Some concerns; ROSEL | Tumor stage: N (%) | T0: 1 (9); T1: 9 (82); T2:1 (9) | Not available | -
Louie, 2015^14^; Some concerns; ROSEL | *Reduction in quality of life | 8/10 | 2/9 | HR = 0.19; p = 0.038

Notes.

* Quality of life data were not reported from 3 participants.

Abbreviations. HR=hazard ratio; ROSEL=Trial of Either Surgery or Stereotactic Radiotherapy for Early Stage (IA) Lung Cancer; SABR=stereotactic ablative radiotherapy.

## KEY QUESTION 3

KQ3: What are the quantity and characteristics of evidence assessing the comparative effects of ablative therapies as monotherapy or combined with other ablative therapies versus surgical, radiotherapy or ablative therapies for patients with early stage I non-small cell lung cancer, by type of intervention, patient/tumor characteristics, study design, and outcomes?

### Literature Flow

The literature flow diagram (Figure 2) summarizes the results of the study selection process. The full list of excluded studies is available in Appendix B.

### Literature Overview

Of 3,095 potentially relevant citations after title and abstract screening, 131 were moved forward to full-text review. Of those 131, we identified 18 publications which met inclusion criteria for KQ3.

### Data Visualization

#### Study Characteristics and Patient Population (Map 1)

No RCTs of ablation therapy were identified from our review; all the included studies were observational studies with a comparator group. Most publications were observational single-site retrospective cohort studies (k = 10),^15–24^ while fewer used multisite retrospective data (k = 2).^25,26^

The majority of the publications on ablative therapies were conducted in the US (k = 9)^15,17,24,27–32^; other countries included China (k = 3),^18,23,26^ Japan (k = 2),^19,25^ Italy (k = 2),^16,21^ South Korea (k = 1)20 and Germany (k = 1).22 Six publications used national US databases, including the National Cancer Database (NCDB) (k = 4)^27,28,30,32^ and the Surveillance, Epidemiology and End-Results Database (SEER) (k = 2).^29,31^ The sample size for the majority of studies was small (range 22–289), with the exception of the 6 large national database studies which included several thousand patients. Detailed information about characteristics for each publication can be found in Table 6.

All of the studies included older adults (mean or median age >60), with only 2 reporting a median or mean age <60.^26,32^ Most studies did not report on whether participants treated with various ablative treatments were felt to be medically operable or inoperable (k = 8)^19,21,23,26–28,30,32^ or reported including both medically operable and inoperable patients (k = 5).^17,18,20,22,25^ Only 2 studies reported on only medically operable individuals (k = 2)^15,29^ and 3 studies reported on only medically inoperable individuals (k = 3).^16,24,31^ None of the studies were conducted in Veterans. While most studies reported some information about tumor characteristics, there was no consistency across studies on which characteristics were reported. There was heterogeneity in reporting of tumor size (mean, median, or range provided) and cancer stage.

#### Interventions and Comparisons (Map 2)

In general, across studies, ablation was compared with surgery or radiotherapy. No studies of brachytherapy compared to surgery or radiotherapy (or other ablative therapies) were found. The interventions and comparisons for each study fell into 6 distinct comparison groups:

- ablation (type not specified or multiple types [cryoablation, laser ablation, radiofrequency ablation, microwave ablation] combined) versus radiotherapy (k = 3)^27,28,32^;
- radiofrequency ablation versus radiotherapy (k = 3)^25,30,31^;
- ablation (type not specified or multiple types combined) versus surgery (k = 2)^24,29^;
- microwave ablation versus surgery (k = 4)^18,21,23,26^;
- radiofrequency ablation versus surgery (k = 4)^15–17,21^;
- radiotherapy versus radiofrequency ablation versus surgery (k = 2).^19,22^

Figure 3 shows the outcomes reported by comparisons made, and Figure 4 shows the outcomes reported, comparisons made, type of data used, and sample size for each publication.

#### Outcomes (Map 3)

With respect to outcomes, all publications reported overall survival (k = 18), most reported on local or regional recurrence (k = 12) and adverse events (k = 11), while fewer reported on lung-cancer-specific survival (k = 8) or distant recurrence (k = 7). We did not identify any publications that reported on quality of life. Figure 3 shows the outcomes that were reported by comparison group. A detailed breakdown of outcomes by study can be found in Table 7, and a detailed breakdown of specific adverse events reported by study can be found in Table 8.

Figure 2 KQ3 Literature Flowchart

Table 6 Detailed Characteristics for Eligible Publications for Key Question 3

Author, Year | Characteristics | | | | Comparisons Analyzed | | | | | | Interventions Included
| Country | Single-site Administrative Data | Multi-site Administrative Data | National Database | Ablation (Combined) vs Radiotherapy | Radiofrequency Ablation vs Radiotherapy | Ablation (Combined) vs Surgery | Microwave vs Surgery | Radiofrequency Ablation vs Surgery | Radiotherapy vs Radiofrequency Ablation vs Surgery | SBRT/SABR | Ablation (Not Specified) | Cryoablation | Radiofrequency Ablation | Microwave Ablation | Laser Ablation | Surgery
Ager, 2019^27^ | US | | | ✓^*^ | ✓ | | | | | | ✓ | ✓ | ✓ | | | ✓
Alexander, 2011^15^ | US | ✓ | | | | | | | ✓ | | | | | ✓ | | | ✓
Ambrogi, 2015^16^ | Italy | ✓ | | | | | | | ✓ | | | | | ✓ | | | ✓
Baine, 2019^28^ | US | | | ✓^*^ | ✓ | | | | | | ✓ | | ✓ | | | ✓
Hsie, 2009^17^ | US | ✓ | | | | | | | ✓ | | | | | ✓ | | | ✓
Hu, 2021^18^ | China | ✓ | | | | | | ✓ | | | | | | | ✓ | | ✓
Iguchi, 2020^19^ | Japan | ✓ | | | | | | | | ✓ | ✓ | | | ✓ | | | ✓
Kim, 2012^20^ | South Korea | ✓ | | | | | | | ✓ | | | | | ✓ | | | ✓
Kwan, 2014^29^ | US | | | ✓^†^ | | | ✓ | | | | | ✓ | | | | | ✓
Lam, 2018^30^ | US | | | ✓^*^ | | ✓ | | | | | ✓ | | | ✓
Li, 2021^31^ | US | | | ✓^†^ | | ✓ | | | | | ✓ | | | ✓
Mendogni, 2020^21^ | Italy | ✓ | | | | | | ✓ | | | | | | | ✓ | | ✓
Ochiai, 2015^25^ | Japan | | ✓ | | | ✓ | | | | | ✓ | | | ✓
Safi, 2015^22^ | Germany | ✓ | | | | | | | | ✓ | ✓ | | | ✓ | | | ✓
Uhlig, 2018^32^ | US | | | ✓^*^ | ✓ | | | | | | ✓ | | ✓ | ✓ | | ✓
Wang, 2018^23^ | China | ✓ | | | | | | ✓ | | | | | | | ✓ | | ✓
Yao, 2018^26^ | China | | ✓ | | | | | ✓ | | | | | | | ✓ | | ✓
Zemlyak, 2010^24^ | US | ✓ | | | | | ✓ | | | | | | ✓ | ✓ | | | ✓

Notes.

* National Cancer Database (NCDB)

† Surveillance, Epidemiology and End-Results Database (SEER)

Figure 3 Outcomes Reported by Comparisons

Notes. Combined indicates authors reported on outcomes based on different types of ablative therapy and not separately by specific ablative therapies.

Abbreviations. MWA=microwave ablation; RFA=radiofrequency ablation.

Figure 4 Evidence Map of Publications Reporting Ablation versus Radiotherapy or Ablation versus Surgery

Table 7 Outcomes Reported by Eligible Publications for Key Question 3

Author, Year | Overall Survival | Lung-cancer-specific Survival | Local/Regional Recurrence | Systemic/Distant Recurrence | Any Adverse Events | Quality of Life | Short-term Cardiovascular Complications | Short-term Respiratory Complications | Long-term Respiratory Complications | Hospital Readmissions
Ager, 2019^27^ | ✓
Alexander, 2011^15^ | ✓ | ✓ | ✓
Ambrogi, 2015^16^ | ✓ | ✓ | ✓ | ✓ | ✓ | | ✓ | ✓
Baine, 2019^28^ | ✓
Hsie, 2009^17^ | ✓ | | ✓ | ✓ | ✓ | | | ✓
Hu, 2021^18^ | ✓ | | ✓ | | ✓ | | ✓ | ✓
Iguchi, 2020^19^ | ✓ | | ✓ | | ✓ | | ✓ | ✓
Kim, 2012^20^ | ✓ | | ✓ | ✓ | ✓ | | | ✓
Kwan, 2014^29^ | ✓ | ✓
Lam, 2018^30^ | ✓
Li, 2021^31^ | ✓ | ✓
Mendogni, 2020^21^ | ✓ | ✓ | ✓ | ✓
Ochiai, 2015^25^ | ✓ | | ✓ | ✓ | ✓ | | | ✓
Safi, 2015^22^ | ✓ | | ✓ | | ✓ | | ✓ | ✓ | ✓ | ✓
Uhlig, 2018^32^ | ✓ | | | | ✓ | | | | | ✓
Wang, 2018^23^ | ✓ | ✓ | ✓ | | ✓ | | | ✓
Yao, 2018^26^ | ✓ | ✓ | ✓ | ✓ | ✓ | | ✓ | ✓
Zemlyak, 2010^24^ | ✓ | ✓ | ✓ | ✓ | ✓ | | | ✓

Table 8 Specific Adverse Events Reported by Eligible Publications for Key Question 3

Author, Year | Short-term Cardiovascular Adverse Events | | | | | | | Short-term Respiratory Adverse Events | | | | | | | | Long-term Respiratory Adverse Events
| Atrial Fibrillation | Pulmonary Arterial Thrombosis | Myocardial Ischemia | Heart Failure | Pulmonary Embolism | Myocardial Infarction | Cardiac Arrest | Pneumonia | Chest Tube | Pneumothorax | Pleural Effusion | Pneumonitis | Respiratory Failure | Hemothorax | Air Leak | Pneumonia | Dyspnea | Pleural Effusion | Pneumonitis | Hemothorax
Ager, 2019^27^
Alexander, 2011^15^
Ambrogi, 2015^16^ | ✓ | | | | | | | | | ✓
Baine, 2019^28^
Hsie, 2009^17^ | | | | | | | | | | ✓
Hu, 2021^18^ | ✓ | | | | | | | ✓ | ✓ | ✓ | ✓ | | | ✓
Iguchi, 2020^19^ | | ✓ | | | | | | | | ✓ | ✓ | ✓
Kim, 2012^20^ | | | | | | | | | | ✓
Kwan, 2014^29^
Lam, 2018^30^
Li, 2021^31^
Mendogni, 2020^21^
Ochiai, 2015^25^ | | | | | | | | | | ✓ | ✓
Safi, 2015^22^ | ✓ | | | | | | | | ✓ | ✓ | ✓ | | | ✓ | | | | ✓ | ✓ | ✓
Uhlig, 2018^32^
Wang, 2018^23^ | | | | | | | | | | ✓ | ✓ | | ✓
Yao, 2018^26^ | ✓ | | ✓ | ✓ | | | | | | ✓ | ✓ | | ✓
Zemlyak, 2010^24^ | | | | | | | | | | ✓ | ✓