# METHODS

## TOPIC DEVELOPMENT

In collaboration with our VA Operational Partners and a technical expert panel (TEP), we developed the key questions and refined the scope of this review. Specifically, while the original protocol focused on surgery compared with non-surgical modalities for patients with stage I lung cancer, the scope of the review was expanded to include an evidence map. The evidence map would outline the body of evidence for comparative studies of ablation therapies in lung cancer, acknowledging the rapidly expanding role for ablation therapy for this indication. Furthermore, comparative effectiveness (and harm) studies for 2 (or more) treatment regimens are best evaluated through randomized head-to-head comparisons, as the body of evidence for comparative effectiveness from observational studies is fraught with issues around confounding (selection bias, performance bias, detection bias) that cannot be fully accounted for using statistical techniques, such as propensity matching. In consultation with our stakeholders and to meet the needs of the National Radiation Oncology Program, the decision was made to include only randomized trials for Key Questions (KQs) 1 and 2. Therefore, this review consists of two parts: 1) a comparative effectiveness review of RCTs comparing surgery to SBRT for stage I non-small cell lung cancer in medically operable patients, and 2) an evidence map of available evidence comparing ablative therapies to other ablative therapies or surgery in either medically operable or inoperable patients.

The term ablation can be used to encompass a wide variety of treatment strategies, but in the context of our review, we specifically looked at the following therapies: radiofrequency ablation, cryoablation, microwave ablation, laser ablation, and brachytherapy. Acknowledging that SABR treatment is categorized as an ablative therapy (or implies ablative intent), the published literature suggests that SBRT and SABR are often used interchangeably and without distinction.^7^ While SBRT is a broad term used to describe the treatment modality itself, SABR is a better descriptor for the specific treatment that consists of applying highly dose-intensive radiation therapy to limited-volume targets with the effect of achieving local tumor control and even cure.^8^ For the purposes of this review, our key questions (and protocol) use the broader term SBRT to encompass both SBRT and SABR, but within the Results and Discussion we use the terms SBRT or SABR as reported by the authors of the primary studies.

The term medically operable was not defined a priori and we relied on the definition used by the individual studies as their predefined inclusion criteria for enrollment into the study. For the evidence map, we describe the population as reported in the primary studies and included individuals with medically operable as well as medically inoperable lung cancer.

## KEY QUESTIONS

The following key questions were the focus of this review:

KQ1 Among adults with medically operable stage I non-small cell lung cancer, what are the benefits and harms of SBRT compared to surgery?
KQ2 Do benefits and harms of SBRT/SABR compared to surgery differ by patient characteristics (eg, age, comorbidities, performance status), tumor characteristics (size, location, stage), surgery characteristics (type of surgery [minimally invasive vs open], type of resection [lobectomy, wedge resection, segmental resection, sleeve resection]), or SBRT characteristics (eg, dose, fractionation)?
KQ3 What are the quantity and characteristics of evidence assessing the comparative effects of ablative therapies as monotherapy or combined with other ablative therapies versus surgical, radiotherapy, or ablative therapies for patients with early stage I non-small cell lung cancer, by type of intervention, patient/tumor characteristics, study design, and outcomes?

## PROTOCOL

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (http://www.crd.york.ac.uk/PROSPERO/; registration number CRD42022377940).

## DATA SOURCES AND SEARCHES

Two search strategies were developed, one to address KQs 1 and 2, and a second for KQ3. We searched MEDLINE and Embase from inception to September 2022. We supplemented these searches with a review of relevant systematic review bibliographies. Relevant systematic reviews were identified by keyword searches of the AHRQ, Cochrane, and VA ESP databases, suggestions by content experts, or reviews found and noted during abstract triage. We limited the searches to published and indexed articles involving human subjects available in the English language (see Appendix A for complete search strategies).

## STUDY SELECTION

After duplicates were removed, citations were uploaded into DistillerSR.^9^ Using prespecified inclusion/exclusion criteria as described below in Table 1 for each KQ, titles and abstracts were screened independently by at least 1 reviewer for potential relevance. Any article excluded at the abstract level required confirmation by a second reviewer; articles included by either reviewer were advanced to the full-text review stage. At the full-text screening stage, 2 independent reviewers agreed on the final inclusion and exclusion decision. Disagreements were resolved by consensus among the review team. Articles that met eligibility criteria were included for data abstraction. A PRISMA flowchart documents the process of study selection and the total number of identified, included, and excluded studies. A complete list of citations excluded at full-text review can be found in Appendix B.

Table 1 Eligibilty Criteria

| Key Questions 1 and 2 | Key Question 3
Population | Adults, 18 years or older, with medically operable stage I non-small cell lung cancer | Adults, 18 years or older, with medically operable or inoperable stage I non-small cell lung cancer
Intervention | Stereotactic body radiation therapy (SBRT)/stereoablative radiation therapy (SABR) | Non-surgical ablative treatment modalities:; - Cryoablation; - Radiofrequency ablation; - Microwave ablation; - Laser ablation; - Brachytherapy
Comparator | Surgery, including wedge resection, segmental resection, lobectomy (including sleeve resection) | - Surgery, including wedge resection, segmental resection, lobectomy (including sleeve resection); - Ablative therapies: cryoablation, radiofrequency ablation, microwave ablation, laser ablation, brachytherapy; - Radiotherapy (SBRT/SABR and conventional)
Outcomes | - Overall survival; - Lung-cancer-specific survival; - Local/regional recurrence/control; - Systemic/distant recurrence/control; - Overall/global quality of life; - SBRT toxicity (grade 2-5 cough, pneumonitis, esophagitis); - Hospital readmissions; - Short-term (<30 days) respiratory complications (pneumonia, hemothorax, pneumothorax, air leak, oxygen dependence at discharge); - Short-term (<30 days) cardiovascular complications (pneumonia, hemothorax, pneumothorax, air leak, oxygen dependence at discharge); - Long-term (>30 days) respiratory complications (cough, pneumonia, dyspnea, oxygen dependence); - Long-term (>30 days) pain (requiring medical intervention) | - Overall survival; - Lung-cancer-specific survival; - Local/regional recurrence/control; - Systemic/distant recurrence/control; - Overall/global quality of life; - Lung cancer specific quality of life validated scale item; - SBRT toxicity (grade 2-5 cough, pneumonitis, esophagitis); - Hospital readmissions; - Short-term (<30 days) respiratory complications (cough, pneumonia, hemothorax, pneumothorax, air leak, oxygen dependence at discharge); - Short-term (<30 days) cardiovascular complications (pneumonia, hemothorax, pneumothorax, air leak, oxygen dependence at discharge); - Post-ablative syndrome; - Long-term (>30 days) respiratory complications (cough, pneumonitis, pneumonia, dyspnea, oxygen dependence)
Timing | Any | Any
Setting | Clinical | Clinical
Study Design | RCTs | RCTs and observational studies with a comparative arm

Abbreviations. RCT=randomized controlled trial.

## DATA ABSTRACTION AND ASSESSMENT

Data from eligible studies were abstracted into customized DistillerSR databases by 1 reviewer and verified by a second reviewer. Any disagreements were resolved by consensus between the 2 reviewers or arbitrated by the study team.

For KQs 1 and 2, we abstracted the following information: trial characteristics (eg, inclusion/exclusion criteria), sample size, intervention and comparison characteristics, demographic information (eg, age, tumor stage), surgery characteristics, SBRT characteristics, and any information related to outcomes of interest. In addition to data from published articles, trial investigators were contacted and asked to provide data stratified by treatment arm (if available) to supplement the published data.

Two reviewers independently assessed risk of bias (RoB) using the Cochrane RoB 2 tool and resolved disagreements via discussion and consensus amongst the review team.10 For each study, we assessed the risk of bias for each domain as being low, high, or unclear. Ratings for all eligible studies for KQs 1 and 2 can be found in Appendix C.

For KQ3, we abstracted the following information: sample size, interventions and comparisons, demographic information (eg, age), country, study design, surgery and ablation therapy characteristics, and outcomes reported. As KQ3 consisted of an evidence map, no formal risk of bias assessment was performed for studies meeting eligibility criteria.

## SYNTHESIS

For KQs 1 and 2, we identified a publication that conducted a quantitative analysis of data from the 2 trials and used this to inform our review. We evaluated the overall certainty of evidence for each outcome according to the GRADE approach, which considers 5 criteria (risk of bias, inconsistency, imprecision, publication bias, and indirectness). One author independently rated the certainty of evidence for each outcome as high, moderate, low, or very low using GRADEpro GDT.^11,12^ Any disagreement was resolved through group consensus. We evaluated the certainty of evidence for the following outcomes: overall survival, lung-cancer-specific survival, quality of life, and adverse events of grade 2 or higher. The summary of the evidence for the main outcomes is presented in a summary of findings table (Table 4), which provides key information regarding the best estimate of the magnitude of the effect in relative and absolute differences for each comparison of alternative management strategy, number of participants and studies, addressing each outcome, and a rating of the overall confidence in the estimates for each outcome.

For KQ3, we relied on data visualization techniques to summarize the data for the evidence map. No formal synthesis of study results was performed and no assessment of the quality of individuals studies was conducted. We summarized the data narratively and provided visual graphics including tables and a bubble plot to summarize the key features of the studies. We mapped the results by types of studies, types of interventions versus comparisons, and types of outcomes. We used Microsoft Excel to create the figures and tables. We sought and iteratively incorporated feedback on visualization and usability from our review team.