# INTRODUCTION

Lung cancer is the leading cause of cancer-related deaths in the United States (US), with an estimated 238,340 new cases of lung cancers expected in 2023 and 127,070 estimated deaths.1 The majority of lung cancers are diagnosed at advanced stages, but with the advent of lung cancer screening, the number of individuals diagnosed with early-stage lung cancer has continued to rise.2 Within the Veterans Health Administration (VA),3 approximately 8,000 Veterans are diagnosed with and treated for lung cancer every year. Non-small cell lung cancer (NSCLC) represents approximately 80–85% of lung cancers and includes the following subtypes: adenocarcinoma, squamous cell carcinoma, and large cell lung cancer. With a median age at diagnosis of 70 years, many individuals diagnosed with NSCLC have comorbid conditions due to advanced age and longstanding tobacco use, which may influence the choice of treatment as well as impact patient-important outcomes.

Surgery has been considered the standard of care for individuals with early-stage lung cancer who are deemed medically operable.^4^ Surgical treatment includes lobectomy, segmentectomy, wedge resection, and sleeve resection with or without the use of minimally invasive approaches such as robotic or video-assisted thoracoscopic surgery (VATS). Stereotactic body radiation therapy (SBRT) or stereotactic ablative radiotherapy (SABR) are frequently offered to individuals considered to be medically inoperable for various reasons, including advanced age, inadequate pulmonary reserve, and multiple comorbidities that place them at high risk for severe perioperative complications. Promising results with SBRT/SABR in medically inoperable patients have led to studies evaluating the efficacy and long-term outcomes of SBRT/SABR in medically operable patients, thus raising questions about the optimal treatment approach for early-stage lung cancer.

This review addresses important questions regarding the comparative effectiveness and harms of surgery versus SBRT/SABR, as well as the role of ablative therapies such as radiofrequency ablation, cryoablation, microwave ablation, laser ablation, and brachytherapy in the management of medically operable stage I lung cancer. This is a priority for the VA considering the burden of lung cancer within the VA health care system and the increased number of diagnoses of stage I lung cancer with lung cancer screening. Furthermore, current US Preventive Services Task Force (USPSTF) recommendations for the decision to pursue lung cancer screening are contingent on an individual’s ability or willingness to have curative lung surgery.^5^ The role of SBRT/SABR in the context of screening decisions or treatment options following a screen-detected or incidentally detected lung cancer is not well outlined but is very relevant to clinical practice and policy decisions. This topic, nominated by the National Radiation Oncology Program, reviews the evidence for the optimal treatment for stage I lung cancer and provides the background rationale for an ongoing VA Cooperative Study, a randomized trial of surgery versus SBRT that is currently enrolling participants.^6^ Findings from this review will be used to inform the evidence on the use of treatment modalities in patients with stage I lung cancer who are deemed medically operable.