# APPENDIX C RISK OF BIAS RATINGS (KQ1 ONLY)

Publication | Trial | Domain 1: Risk of Bias Arising from the Randomization Process | Domain 2a: Risk of Bias Due to Deviations from the Intended Interventions (Effect of Assignment to Intervention) | Domain 2b: Risk of Bias Due to Deviations from the Intended Interventions (Effect of Adherence to Intervention) | Domain 3: Risk of Bias Due to Missing Outcome Data | Domain 4: Risk of Bias in Measurement of the Outcome | Domain 5: Risk of Bias in Selection of the Reported Result | Overall Risk of Bias
Chang, 2015^13^ | STARS NCT00840749 (https://clinicaltrials.gov/ct2/show/NCT00840749) | Low | Low | Low | Low | Low | Some concerns | Some concerns
Chang, 2015^13^ | ROSEL NCT00687986 (https://clinicaltrials.gov/ct2/show/NCT00687986) | Low | Low | Low | Low | Low | Some concerns | Some concerns
Louie, 2015^14^ | ROSEL NCT00687986 (https://clinicaltrials.gov/ct2/show/NCT00687986) | Low | Low | Low | Low | Some concerns | Low | Some concerns

Abbreviations. ROSEL=Trial of Either Surgery or Stereotactic Radiotherapy for Early Stage (IA) Lung Cancer; STARS=Randomized Study to Compare CyberKnife to Surgical Resection in Stage I Non-small Cell Lung Cancer.