# APPENDIX B EXCLUDED STUDIES

## KEY QUESTIONS 1 & 2

1 Aridgides P, Bogart J. Stereotactic Body Radiation Therapy for Stage I Non-Small Cell Lung Cancer. Thoracic Surgery Clinics. 2016;26(3):261–269. Ineligible publication type27427521
2 Bahig H, Chen H, Louie AV. Surgery versus SABR for early stage non-small cell lung cancer: The moving target of equipoise. Journal of Thoracic Disease. 2017;9(4):953–956. Ineligible publication type28523146
3 Chen W, Lin Q, Sun X, A propensity-matched analysis of stereotactic body radiotherapy and sublobar resection for stage I non-small cell lung cancer in patients at high risk for lobectomy. Journal of Clinical Oncology. 2017;35(15 Supplement 1). Ineligible study design
4 Choy H, Chakravarthy A, Kim JS. Radiation therapy for non-small cell lung cancer (NSCLC). Cancer treatment and research. 2001;105:121–48. Ineligible publication type11224985
5 Fernando HC, Timmerman R. American College of Surgeons Oncology Group Z4099/Radiation Therapy Oncology Group 1021: a randomized study of sublobar resection compared with stereotactic body radiotherapy for high-risk stage I non-small cell lung cancer. The Journal of thoracic and cardiovascular surgery. 2012;144(3):S35–8. Ineligible publication type22795435
6 Franks KN, McParland L, Webster J, SABRTooth: a randomised controlled feasibility study of stereotactic ablative radiotherapy (SABR) with surgery in patients with peripheral stage I nonsmall cell lung cancer considered to be at higher risk of complications from surgical resection. The European respiratory journal. 2020;56(5). Ineligible outcome
7 Gerard M, Lerouge D, Le Guevelou J, Thariat J. Stereotaxic ablative radiotherapy in stage 1 non-small-cell lung cancer: Results of the phase 3 randomized trial "CHISEL". Bulletin du Cancer. 2020;107(2):145–147. Ineligible language
8 Guckenberger M. SBRT versus lobectomy in stage I NSCLC: Knowns, unknowns and its interpretation. Journal of Thoracic Disease. 2016;8(9):2305–2309. Ineligible publication type27746961
9 Hansen O, Knap MM, Khalil A, A randomized phase II trial of concurrent chemoradiation with two doses of radiotherapy, 60Gy and 66Gy, concomitant with a fixed dose of oral vinorelbine in locally advanced NSCLC. Radiotherapy and oncology: journal of the European Society for Therapeutic Radiology and Oncology. 2017;123(2):276–281. Ineligible intervention28410809
10 Herrmann MK A, Bloch E, Overbeck T, Mediastinal radiotherapy after multidrug chemotherapy and prophylactic cranial irradiation in patients with SCLC--treatment results after long-term follow-up and literature overview. Cancer radiotherapie: journal de la Societe francaise de radiotherapie oncologique. 2011;15(2):81–8. Ineligible intervention20708424
11 Love SM, Hardman G, Mashar R, Shah RD. Is it time for SABR to overtake surgery as the treatment of choice for stage I non-small cell lung cancer? Annals of Translational Medicine. 2016;4(24):535. Ineligible publication type28149896
12 Macchi M, Belfiore MP, Floridi C, Radiofrequency versus microwave ablation for treatment of the lung tumours: LUMIRA (lung microwave radiofrequency) randomized trial. Medical Oncology. 2017;34(5):96. Ineligible intervention28417355
13 Nieder C, Andratschke NH, Guckenberger M. A pooled analysis of stereotactic ablative radiotherapy versus lobectomy for operable stage I non-small cell lung cancer: is failure to recruit patients into randomized trials also an answer to the research question? Annals of translational medicine. 2015;3(11):148. Ineligible publication type26244135
14 Onaitis MW, Salama J. Surgery versus stereotactic body radiation therapy for operable stage i non-small cell lung cancer: Can we achieve equipoise? Journal of Thoracic and Cardiovascular Surgery. 2016;152(1):1–2. Ineligible publication type27343902
15 Parashar B, Port J, Arora S, Analysis of stereotactic radiation vs. wedge resection vs. wedge resection plus Cesium-131 brachytherapy in early stage lung cancer. Brachytherapy. 2015;14(5):648–54. Ineligible study design25998071
16 Robinson C, Kruser TJ, Owen D, Salama J, Daly ME. Fast and Furious: New Data Examining Accelerated Radiation Therapy for Limited-Stage Small Cell Lung Cancer. International Journal of Radiation Oncology Biology Physics. 2022;112(5):1067–1070. Ineligible publication type35286875
17 Roesch J, Andratschke N, Guckenberger M. SBRT in operable early stage lung cancer patients. Translational lung cancer research. 2014;3(4):212–24. Ineligible publication type25806303
18 Rusthoven CG, Kavanagh BD, Karam SD. Improved survival with stereotactic ablative radiotherapy (SABR) over lobectomy for early stage non-small cell lung cancer (NSCLC): addressing the fallout of disruptive randomized data. Annals of translational medicine. 2015;3(11):149. Ineligible publication type26244136
19 Samson P, Keogan K, Crabtree T, Interpreting survival data from clinical trials of surgery versus stereotactic body radiation therapy in operable Stage I non-small cell lung cancer patients. Lung cancer (Amsterdam, Netherlands). 2017;103:6–10. Ineligible study design28024698
20 Seo Y- S, Kim HJ, Wu HG, Choi SM, Park S. Lobectomy versus stereotactic ablative radiotherapy for medically operable patients with stage IA non-small cell lung cancer: A virtual randomized phase III trial stratified by age. Thoracic cancer. 2019;10(6):1489–1499. Ineligible study design31124275
21 Sepesi B, Rice DC, Heymach JV, Vaporciyan AA, Swisher SG. Stage I lung cancer-to operate or to radiate? That is the question. Journal of Thoracic Disease. 2016;8(9):2324–2327. Ineligible publication type27746966
22 Shi XX, Pang HW, Ren PR, Sun XY, Wu JB, Lin S. Template-assisted192Ir-based stereotactic ablative brachytherapy as a neoadjuvant treatment for operable peripheral non-small cell lung cancer: A phase I clinical trial. Journal of Contemporary Brachytherapy. 2019;11(2):162–168. Ineligible study design31139225
23 Shirvani SM, Chang JY, Roth JA. Can stereotactic ablative radiotherapy in early stage lung cancers produce comparable success as surgery? Thoracic Surgery Clinics. 2013;23(3):369–381. Ineligible publication type23931020
24 Teke ME, Sarvestani AL, Hernandez JM, Fernando HC, Timmerman RD. A Randomized, Phase III Study of Sublobar Resection (SR) Versus Stereotactic Ablative Radiotherapy (SAbR) in High-Risk Patients with Stage I Non-Small Cell Lung Cancer (NSCLC). Annals of surgical oncology. 2022;29(8):4686–4687. Ineligible publication type35524087
25 Videtic GM, Paulus R, Singh AK, Long-term Follow-up on NRG Oncology RTOG 0915 (NCCTG N0927): A Randomized Phase 2 Study Comparing 2 Stereotactic Body Radiation Therapy Schedules for Medically Inoperable Patients With Stage I Peripheral Non-Small Cell Lung Cancer. International journal of radiation oncology, biology, physics. 2019;103(5):1077–1084. Ineligible intervention30513377

## KEY QUESTION 3

1 Abdel-Aaty H, Bakr R, El-Mahallawy I, El-Helbawy R, Hussein S, Abdel-Tawab A. Cryotherapy and electrocautery in the management of malignant endobronchial neoplasms. Egyptian Journal of Chest Diseases and Tuberculosis. 2019;68(2):184–191. Ineligible population
2 Alexander ES, Hankins CA, MacHan JT, Healey TT, Dupuy DE. Rib fractures after percutaneous radiofrequency and microwave ablation of lung tumors: Incidence and relevance. Radiology. 2013;266(3):971–978. Ineligible outcome23315659
3 Ambrogi MC, Dini P, Melfi F, Mussi A. Radiofrequency ablation of inoperable non-small cell lung cancer. Journal of Thoracic Oncology. 2007;2(5 SUPPL.1):S2–S3. Ineligible outcome17457225
4 Ambrogi MC, Fontanini G, Cioni R, Faviana P, Fanucchi O, Mussi A. Biologic effects of radiofrequency thermal ablation on non-small cell lung cancer: Results of a pilot study. Journal of Thoracic and Cardiovascular Surgery. 2006;131(5):1002–1006. Ineligible population16678582
5 Amjadi K, Voduc N, Cruysberghs Y, Impact of interventional bronchoscopy on quality of life in malignant airway obstruction. Respiration. 2008;76(4):421–428. Ineligible intervention18758153
6 Asimakopoulos G, Beeson J, Evans J, Maiwand MO. Cryosurgery for malignant endobronchial tumors: Analysis of outcome. Chest. 2005;127(6):2007–2014. Ineligible population15947313
7 Aufranc V, Farouil G, Abdel-Rehim M, Percutaneous thermal ablation of primary and secondary lung tumors: Comparison between microwave and radiofrequency ablation. Diagnostic and Interventional Imaging. 2019;100(12):781–791. Ineligible population31402333
8 Baisi A, Raveglia F, De Simone M, Cioffi U. Recurrence after radiofrequency ablation for stage i non-small cell lung cancer. Annals of Thoracic Surgery. 2012;94(5):1788–1789. Ineligible study design
9 Beland M, Mueller PR, Gervais DA. Thermal Ablation in Interventional Oncology. Seminars in Roentgenology. 2007;42(3):175–190. Ineligible study design17599551
10 Birdas TJ, Koehler RP M, Colonias A, Sublobar resection with brachytherapy versus lobectomy for stage Ib nonsmall cell lung cancer. Annals of Thoracic Surgery. 2006;81(2):434–439. Ineligible intervention16427827
11 Botsa EI, Thanou IL, Papatheodoropoulou AT, Thanos LI. Thermal ablation in the management of adrenal metastasis originating from non-small cell lung cancer: A 5-year single-center experience. Chinese Medical Journal. 2017;130(17):2027–2032. Ineligible population28707652
12 Cackler S, Abbas G. RFA is an effective alternative to lobectomy for lung cancer. JAAPA: official journal of the American Academy of Physician Assistants. 2009;22(1):25–8. Ineligible study design19248357
13 Canak V, Zaric B, Milovancev A, Combination of interventional pulmonology techniques (Nd:YAG laser resection and brachytherapy) with external beam radiotherapy in the treatment of lung cancer patients with Karnofsky Index <= 50. Journal of BUON. 2006;11(4):447–456. Ineligible intervention17309176
14 Carrafiello G, Mangini M, Fontana F, Complications of microwave and radiofrequency lung ablation: personal experience and review of the literature. La Radiologia medica. 2012;117(2):201–213. Ineligible study design22020434
15 Chella A, Ambrogi MC, Ribechini A, Combined Nd-YAG laser/HDR brachytherapy versus Nd-YAG laser only in malignant central airway involvement: A prospective randomized study. Lung Cancer. 2000;27(3):169–175. Ineligible intervention10699690
16 Chen S, Sheng Z, Huang N. Radiofrequency Ablation Combined with Radioactive Seed Implantation for Nonsmall Cell Lung Cancer. Journal of healthcare engineering. 2022;2022:4016081. Ineligible population35356608
17 Chi J, Ding M, Shi Y, Comparison study of computed tomography-guided radiofrequency and microwave ablation for pulmonary tumors: A retrospective, case-controlled observational study. Thoracic Cancer. 2018;9(10):1241–1248. Ineligible population30070054
18 Choe YH, Kim SR, Lee KS, The use of PTC and RFA as treatment alternatives with low procedural morbidity in non-small cell lung cancer. European Journal of Cancer. 2009;45(10):1773–1779. Ineligible population19285385
19 Choe YH, Rhee YK, Park SJ, Therapeutic value of image-guided ablations as treatment alternatives in non-small cell lung cancer. Respirology. 2009;14(SUPPL. 3):A248. Ineligible publication type
20 Crabtree T, Puri V, Timmerman R, Treatment of stage I lung cancer in high-risk and inoperable patients: comparison of prospective clinical trials using stereotactic body radiotherapy (RTOG 0236), sublobar resection (ACOSOG Z4032), and radiofrequency ablation (ACOSOG Z4033). The Journal of thoracic and cardiovascular surgery. 2013;145(3):692–9. Ineligible intervention23174176
21 D'Amico TA. Local control without resection. The Journal of thoracic and cardiovascular surgery. 2003;125(4):787–8. Ineligible publication type12698140
22 Davis JN, Medbery C, Sharma S, Danish A, Mahadevan A. The RSSearchTM Registry: Patterns of care and outcomes research on patients treated with stereotactic radiosurgery and stereotactic body radiotherapy. Radiation Oncology. 2013;8(1):275. Ineligible population24274599
23 DiRico M, Roy SG, Berry G, Brahmakulam F. RADIOFREQUENCY AND CRYOABLATION FOR MALIGNANT LUNG NODULES IN A COMMUNITY SETTING. Chest. 2020;158(4 Supplement):A1947. Ineligible publication type
24 Donington JS. Radiofrequency ablation in high-risk stage i non-small cell lung cancer. Cancer. 2015;121(19):3393–3394. Ineligible publication type26096602
25 Dupuy D, Fernando H, Hillman S, Radiofrequency ablation of stage 1A NSCLC in medically inoperable patients: Results from ACOSOG Z4033 (Alliance), an NCI funded multicenter trial. Chest. 2013;144(4 MEETING ABSTRACT). Ineligible publication type
26 Dupuy DE. Science to practice: Microwave ablation compared with radiofrequency ablation in lung tissue - Is microwave not just for popcorn anymore? Radiology. 2009;251(3):617–618. Ineligible publication type19474368
27 Dupuy DE. Treatment of medically inoperable non-small-cell lung cancer with stereotactic body radiation therapy versus image-guided tumor ablation: can interventional radiology compete? Journal of vascular and interventional radiology: JVIR. 2013;24(8):1139–45. Ineligible study design23796858
28 Dupuy DE, Fernando HC, Hillman S, Radiofrequency ablation of stage IA non-small cell lung cancer in medically inoperable patients: Results from the American College of Surgeons Oncology Group Z4033 (Alliance) trial. Cancer. 2015;121(19):3491–3498. Ineligible intervention26096694
29 Dupuy DE, Zagoria RJ, Akerley W, Mayo-Smith WW, Kavanagh PV, Safran H. Percutaneous radiofrequency ablation of malignancies in the lung. AJR American journal of roentgenology. 2000;174(1):57–9. Ineligible study design10628454
30 e Baere T. Another Brick in the Wall: Further Evidence Supporting the Efficacy of Thermal Ablation. CardioVascular and Interventional Radiology. 2020;43(12):1908–1909. Ineligible study design32995938
31 Ezer N, Mhango G, Wisnivesky JP. Radiofrequency ablation vs. conventional radiotherapy for unresected early stage non-small cell lung cancer. American Journal of Respiratory and Critical Care Medicine. 2014;189(MeetingAbstracts). Ineligible publication type
32 Fanucchi O, Ambrogi MC, Dini P, Mussi A. Early stage NSCLC in high risk patients: Wedge resection VS radiofrequency ablation. European Surgical Research. 2010;45(3–4):247. Unable to locate full text
33 Fanucchi O, Ambrogi MC, Melfi FM A, Wedge resection vs. Radiofrequency ablation to treat early stage NSCLC in high-risk patients. Innovations: Technology and Techniques in Cardiothoracic and Vascular Surgery. 2014;9(3):181. Unable to locate full text
34 Fernando HC, Landreneau RJ, Mandrekar SJ, The impact of adjuvant brachytherapy with sublobar resection on pulmonary function and dyspnea in high-risk patients with operable disease: Preliminary results from the American College of Surgeons Oncology Group Z4032 Trial. Journal of Thoracic and Cardiovascular Surgery. 2011;142(3):554–562. Ineligible intervention21724195
35 Fernando HC, Landreneau RJ, Mandrekar SJ, Thirty- and ninety-day outcomes after sublobar resection with and without brachytherapy for non-small cell lung cancer: Results from a multicenter phase III study. Journal of Thoracic and Cardiovascular Surgery. 2011;142(5):1143–1151. Ineligible intervention21872277
36 Fernando HC, Landreneau RJ, Mandrekar SJ, Analysis of longitudinal quality-of-life data in high-risk operable patients with lung cancer: Results from the ACOSOG Z4032 (Alliance) multicenter randomized trial. Journal of Thoracic and Cardiovascular Surgery. 2015;149(3):718–726. Ineligible intervention25500100
37 Fernando HC, Landreneau RJ, Mandrekar SJ, Impact of brachytherapy on local recurrence rates after sublobar resection: Results from ACOSOG Z4032 (alliance), a phase III randomized trial for high-risk operable non-small-cell lung cancer. Journal of Clinical Oncology. 2014;32(23):2456–2462. Ineligible intervention24982457
38 Fernando HC, Santos RS, Benfield JR, Lobar and sublobar resection with and without brachytherapy for small stage IA non-small cell lung cancer. Journal of Thoracic and Cardiovascular Surgery. 2005;129(2):261–267. Ineligible intervention15678034
39 Garnon J, Koch G, Rao P, Optimising Pulmonary Microwave Ablation Using Trans-Scapular Access and Continuous Temperature Monitoring. CardioVascular and Interventional Radiology. 2016;39(5):791–794. Ineligible publication type26817761
40 Ghaye B. Percutaneous ablation of malignant thoracic tumors. JBR-BTR: organe de la Societe royale belge de radiologie (SRBR) = orgaan van de Koninklijke Belgische Vereniging voor Radiologie (KBVR). 2013;96(3):142–54. Ineligible study design23971170
41 Grasso RF, Bernetti C, Pacella G, A comparative analysis of thermal ablation techniques in the treatment of primary and secondary lung tumors: a single-center experience. La Radiologia medica. 2022;127(7):714–724. Ineligible population35701683
42 Haasbeek CJ A, Senan S, Smit EF, Lagerwaard FJ. CT-guided pulmonary radiofrequency ablation [8]. Radiology. 2008;246(1):334. Ineligible study design18096551
43 Han HJ, Park SJ, Kim SR, The comparison of effectiveness between surgical resection and radiofrequency ablation for stage I non-small cell lung cancer. Respirology. 2009;14(SUPPL. 3):A249. Unable to locate full text
44 Healey TT, Dupuy DE. Microwave ablation for lung cancer. Medicine and health, Rhode Island. 2012;95(2):52–3. Ineligible publication type22474876
45 Healey TT, Dupuy DE. Microwave ablation for lung cancer. Medicine and health, Rhode Island. 2012;95(2):52–53. Unable to locate full text22474876
46 Hiraki T, Gobara H, Mimura H, Sano Y, Kanazawa S. Percutaneous radiofrequency ablation of lung cancer. The Lancet Oncology. 2008;9(7):604–605. Ineligible study design18598924
47 Jain SK, Simon CJ, Dupuy DE. Lung radiofrequency ablation. Seminars in Interventional Radiology. 2003;20(4):307–322. Unable to locate full text
48 Jang TW, Blackman G, George JJ. Survival benefits of lung cancer patients undergoing laser and brachytherapy. Journal of Korean medical science. 2002;17(3):341–347. Ineligible population12068137
49 Jin GY, Lee JM, Lee YC, Han YM. Acute Cerebral Infarction after Radiofrequency Ablation of an Atypical Carcinoid Pulmonary Tumor. American Journal of Roentgenology. 2004;182(4):990–992. Ineligible study design15039177
50 Jin GY, Lee JM, Lee YC, Han YM, Lim YS. Primary and secondary lung malignancies treated with percutaneous radiofrequency ablation: evaluation with follow-up helical CT. AJR American journal of roentgenology. 2004;183(4):1013–1020. Ineligible population15385295
51 Kent MS, Mandrekar SJ, Landreneau R, Impact of Sublobar Resection on Pulmonary Function: Long-Term Results from American College of Surgeons Oncology Group Z4032 (Alliance). Annals of Thoracic Surgery. 2016;102(1):230–238. Ineligible outcome27101728
52 Kent MS, Mandrekar SJ, Landreneau R, A Nomogram to Predict Recurrence and Survival of High-Risk Patients Undergoing Sublobar Resection for Lung Cancer: An Analysis of a Multicenter Prospective Study (ACOSOG Z4032). Annals of Thoracic Surgery. 2016;102(1):239–246. Ineligible outcome27101729
53 Kido M, Kuruma H, Sasaki H, Pulmonary metastases after low-dose-rate brachytherapy for localized prostate cancer. Korean Journal of Urology. 2014;55(5):309–314. Ineligible population24868334
54 Kim EY, Kim YS, Kim JH. Thermal ablation for the treatment of primary and secondary pulmonary malignancies. Journal of Thoracic Disease. 2017;9(10):3641–3644. Ineligible publication type29268363
55 Kishi R, Mimura H, Hiraki T, Bleeding into a pulmonary cyst caused by pulmonary radiofrequency ablation. Journal of vascular and interventional radiology: JVIR. 2013;24(7):1069–71. Ineligible study design23796097
56 Kotinsley KA, Betler J, Kotinsley B, Outcome analysis of sublobar resection and intraoperative 125I brachytherapy vs. stereotactic body radiotherapy in stage I non-small cell lung carcinoma. International Journal of Radiation Oncology Biology Physics. 2011;81(2 SUPPL. 1):S162–S163. Ineligible publication type
57 Lam A, Yoshida EJ, Bui K, Patient and Facility Demographics Related Outcomes in Early-Stage Non-Small Cell Lung Cancer Treated with Radiofrequency Ablation: A National Cancer Database Analysis. Journal of Vascular and Interventional Radiology. 2018;29(11):1535–1541.e2. Ineligible intervention30293735
58 Landreneau JP, Schuchert MJ, Abbas G, Segmentectomy and brachytherapy mesh implantation for clinical stage I non-small cell lung cancer (NSCLC). Journal of Surgical Research. 2012;172(2):277–278. Ineligible publication type
59 Landreneau JP, Schuchert MJ, Weyant R, Anatomic segmentectomy and brachytherapy mesh implantation for clinical stage i non-small cell lung cancer (NSCLC). Surgery (United States). 2014;155(2):340–346. Ineligible intervention
60 Lau KK W, Waller DA, Rathinam S, Page R, Peake MD. Lung cancer resection rate is related to survival. Thorax. 2013;68(2):187. Ineligible study design
61 Lee H, Jin GY, Han YM, Comparison of survival rate in primary non-small-cell lung cancer among elderly patients treated with radiofrequency ablation, surgery, or chemotherapy. CardioVascular and Interventional Radiology. 2012;35(2):343–350. Ineligible population21626257
62 Li HW, Long YJ, Yan GW, Microwave ablation vs. cryoablation for treatment of primary and metastatic pulmonary malignant tumors. Molecular and Clinical Oncology. 2022;16(3):62. Ineligible population35154702
63 Li M, Qin Y, Mei A, Wang C, Fan L. Effectiveness of radiofrequency ablation therapy for patients with unresected Stage IA non-small cell lung cancer. Journal of Cancer Research and Therapeutics. 2020;16(5):1007–1013. Ineligible intervention33004741
64 Li R, Ying Z, Yuan Y, Comparison of two iodine-125 brachytherapy implant techniques for the treatment of lung tumor: Preplanning and intraoperative planning. Brachytherapy. 2019;18(1):87–94. Ineligible intervention30482623
65 Li R, Zhang Y, Yuan Y, Dosimetric comparison of CT-guided iodine-125 seed stereotactic brachytherapy and stereotactic body radiation therapy in the treatment of NSCLC. PLoS ONE. 2017;12(11):e0187390. Ineligible outcome29121047
66 Louie AV, Senthi S, Palma DA. Surgery versus SABR for NSCLC. The Lancet Oncology. 2013;14(12):e491. Ineligible study design24176567
67 Louie AV, Siva S, Senan S. Defining the role of radiofrequency ablation and stereotactic ablative radiotherapy in patients with high-risk, early-stage non-small cell lung cancer. Cancer. 2016;122(2):322–323. Ineligible publication type26421800
68 Ma G- W, Pytel M, Trejos AL, Robot-assisted thoracoscopic brachytherapy for lung cancer: comparison of the ZEUS robot, VATS, and manual seed implantation. Computer aided surgery: official journal of the International Society for Computer Aided Surgery. 2007;12(5):270–7. Ineligible intervention17957534
69 Manning M, Sintay B, Wiant D, Ganem P, Moody JS. An overall survival comparison of sub-lobar resection with brachytherapy versus stereotactic body radiation therapy for early-stage non-small cell lung cancer. International Journal of Radiation Oncology Biology Physics. 2013;87(2 SUPPL. 1):S544. Ineligible publication type
70 Mantz CA, Dosoretz DE, Rubenstein JH, Endobronchial brachytherapy and optimization of local disease control in medically inoperable non-small cell lung carcinoma: A matched-pair analysis. Brachytherapy. 2004;3(4):183–190. Ineligible intervention15607149
71 Meade C, Quinn M, Pezzuti R, Dykes T, Gerding J. Predictors of tumor recurrence using positron emission tomography/computed tomography (PET/CT) after radiofrequency ablation of lung malignancies. Journal of Vascular and Interventional Radiology. 2010;21(12):1931. Unable to locate full text
72 Meng M, Huang G, Ye X, Microwave ablation plus recombinant human endostatin (endostar) versus microwave ablation alone in inoperable stage I non small cell lung cancer. Journal of Clinical Oncology. 2018;36(15 Supplement 1). Ineligible publication type
73 Moghanaki D, Karas T. Surgery versus SABR for NSCLC. The Lancet Oncology. 2013;14(12):e490–e491. Ineligible publication type24176566
74 Muto P, Ravo V, Panelli G, Liguori G, Fraioli G. High-dose rate brachytherapy of bronchial cancer: Treatment optimization using three schemes of therapy. Oncologist. 2000;5(3):209–214. Ineligible population10884499
75 Narsule CK, Nair D, Gupta A, Thermal ablation for stage IA non-small cell lung cancer: Long-term follow-up. Innovations: Technology and Techniques in Cardiothoracic and Vascular Surgery. 2014;9(3):181. Unable to locate full text
76 Narsule CK, Sridhar P, Nair D, Percutaneous thermal ablation for stage IA non-small cell lung cancer: Long-term follow-up. Journal of Thoracic Disease. 2017;9(10):4039–4045. Ineligible intervention29268414
77 Niemoeller OM, Pollinger B, Niyazi M, Mature results of a randomized trial comparing two fractionation schedules of high dose rate endoluminal brachytherapy for the treatment of endobronchial tumors. Radiation Oncology. 2013;8(1):8. Ineligible population23289530
78 Oesch A, Kuster R, Schmid RA. Limited resection or radiofrequency ablation for high risk patients. Therapeutische Umschau. 2012;69(7):429–432. Ineligible language22753292
79 Parashar B, Arora S, Christos P, Comparison of wedge resection versus wedge resection plus cesium-131 brachytherapy versus stereotactic body radiation therapy in management of early stage lung cancer patients that are not candidates for a standard lobectomy. International Journal of Radiation Oncology Biology Physics. 2013;87(2 SUPPL. 1):S203–S204. Ineligible publication type
80 Parashar B, Patel P, Monni S, Limited resection followed by intraoperative seed implantation is comparable to stereotactic body radiotherapy for solitary lung cancer. Cancer. 2010;116(21):5047–5053. Ineligible intervention20652951
81 Parashar B, Port J, Arora S, Analysis of stereotactic radiation vs. wedge resection vs. wedge resection plus Cesium-131 brachytherapy in early stage lung cancer. Brachytherapy. 2015;14(5):648–654. Ineligible intervention25998071
82 Patel M, Maraboyina S, Kim T. Brachytherapy vs External Beam Radiation in the Management of Non Small Cell Lung Cancer. Brachytherapy. 2019;18(3 Supplement):S39. Ineligible publication type
83 Patel MA, Fazli Y, Sivakumar S, Brachytherapy vs external beam therapy among NSCLC patients undergoing limited surgical resection. Journal of Cancer Research and Clinical Oncology. 2021;147(3):853–861. Ineligible population32940781
84 Petera J, Neumanova R, Vrba M, HDR intraluminal brachytherapy in the treatment of malignant bronchial obstructions. Neoplasma. 2000;47(1):56–9. Ineligible population10870688
85 Platta S, Kruser TJ, Weigel TL, Sublobar resection with intraoperative 125I brachytherapy vs stereotactic body radiation therapy for treatment of clinical early stage non-small cell lung cancer in patients not eligible for lobectomy. Journal of Thoracic Oncology. 2012;7(9 SUPPL. 4):S227–S228. Ineligible publication type
86 Potter R. Image-guided brachytherapy sets benchmarks in advanced radiotherapy. Radiotherapy and Oncology. 2009;91(2):141–146. Ineligible publication type19427546
87 Pua BB, Thornton RH, Solomon SB. Radiofrequency Ablation: Treatment of Primary Lung Cancer. Seminars in Roentgenology. 2011;46(3):224–229. Ineligible publication type21726706
88 Pusceddu C, Melis L, Fancellu A, Melis M, Meloni G. Feasibility and safety of percutaneous radiofrequency, microwave or cryoablation for unresectable thoracic malignancies in close proximity to heart and large vessels. Annals of Surgical Oncology. 2013;20(1 SUPPL. 1):S106. Ineligible publication type
89 Roy-Choudhury S. Lung alert. Inflammation caused by radiofrequency ablation for lung cancer is worse after radiotherapy and in large tumours. Thorax. 2008;63(11):998. Ineligible study design
90 Safi S, Op Den Winkel J, Rauch G, Outcomes following sublobar resection, radiofrequency ablation or radiotherapy for stage I non-small-cell lung cancer: A retrospective analysis. Interactive Cardiovascular and Thoracic Surgery. 2014;18(SUPPL. 1):S17. Ineligible publication type
91 Sainani NI, Shyn PB, Tatli S, Morrison PR, Tuncali K, Silverman SG. PET/CT-guided radiofrequency and cryoablation: is tumor fluorine-18 fluorodeoxyglucose activity dissipated by thermal ablation? Journal of vascular and interventional radiology: JVIR. 2011;22(3):354–60. Ineligible population21353987
92 Santos R, Colonias A, Parda D, Comparison between sublobar resection and 125Iodine brachytherapy after sublobar resection in high-risk patients with Stage I non-small-cell lung cancer. Surgery. 2003;134(4):691–697. Ineligible intervention14605631
93 Scappaticci AA, Yoo DC. Recurrence of lung cancer after radiofrequency ablation detected by PET/CT and contrast enhanced CT scan. Medicine and health, Rhode Island. 2012;95(5):146–148. Ineligible study design22808632
94 Schneider T, Reuss D, Warth A, The efficacy of bipolar and multipolar radiofrequency ablation of lung neoplasms - results of an ablate and resect study. European Journal of Cardio-thoracic Surgery. 2011;39(6):968–973. Ineligible population20961771
95 Seibold P, Webb A, Aguado-Barrera ME, REQUITE: A prospective multicentre cohort study of patients undergoing radiotherapy for breast, lung or prostate cancer. Radiotherapy and Oncology. 2019;138:59–67. Ineligible population31146072
96 Sharma DN, Rath GK. Brachytherapy for medically inoperable lung cancer. The Lancet Oncology. 2009;10(12):1141–2. Ineligible study design19959072
97 Shi F, Li G, Zhou Z, Microwave ablation versus radiofrequency ablation for the treatment of pulmonary tumors. Oncotarget. 2017;8(65):109791–109798. Ineligible population29312649
98 Shyn PB. Is image-guided thermal ablation ready for treatment of stage 1 non-small cell lung cancer? Radiology. 2018;289(3):871–872. Ineligible publication type30226452
99 Skonieczki BD, Wells C, Wasser EJ, Dupuy DE. Radiofrequency and microwave tumor ablation in patients with implanted cardiac devices: Is it safe? European Journal of Radiology. 2011;79(3):343–346. Ineligible population20434862
100 Skowronek J. Lung cancer brachytherapy. International Journal of Cancer Research and Prevention. 2011;4(2):97–126. Ineligible study design
101 Smith S, Jennings P. Thoracic intervention and surgery to cure lung cancer: image-guided thermal ablation in primary lung cancer. Journal of the Royal Society of Medicine. 2019;112(6):218–225. Ineligible study design29532709
102 Sofocleous CT, Sideras P, Petre EN, Solomon SB. Ablation for the management of pulmonary malignancies. American Journal of Roentgenology. 2011;197(4):W581–W589. Ineligible study design21940530
103 Steinke K, Liu H. Minimally invasive techniques for medically inoperable stage i non-small cell lung cancer (NSCLC) - Image-guided microwave ablation, a promising therapy option. Journal of Medical Imaging and Radiation Oncology. 2014;58(1):79–80. Ineligible publication type24529059
104 Tam TY, Rosenzweig KE, Rimner A, Chronic obstructive pulmonary disease predicts for increased respiratory toxicity in patients with early-stage non-small cell lung cancer treated with stereotactic body radiotherapy. International Journal of Radiation Oncology Biology Physics. 2011;81(2 SUPPL. 1):S591. Ineligible publication type
105 Tselikas L, Garzelli L, Mercier O, Radiofrequency ablation versus surgical resection for the treatment of oligometastatic lung disease. Diagnostic and Interventional Imaging. 2021;102(1):19–26. Ineligible population33020025
106 Venturini M, Cariati M, Marra P, Masala S, Pereira PL, Carrafiello G. CIRSE Standards of Practice on Thermal Ablation of Primary and Secondary Lung Tumours. CardioVascular and Interventional Radiology. 2020;43(5):667–683. Ineligible study design32095842
107 Verstegen NE, Oosterhuis JW A, Palma DA, Stage I-II non-small-cell lung cancer treated using either stereotactic ablative radiotherapy (SABR) or lobectomy by video-assisted thoracoscopic surgery (VATS): outcomes of a propensity score-matched analysis. Annals of oncology: official journal of the European Society for Medical Oncology. 2013;24(6):1543–8. Ineligible population23425947
108 Vogl TJ, Basten LM, Nour-Eldin NE A, Kaltenbach B, Ackermann H, Naguib NN N. Microwave ablation (MWA) of pulmonary neoplasms: Clinical performance of high-frequency MWA with spatial energy control versus conventional low-frequency MWA. American Journal of Roentgenology. 2019;213(6):1388–1396. Ineligible population31593520
109 Vogl TJ, Roman A, Nour-Eldin NE A, Hohenforst-Schmidt W, Bednarova I, Kaltenbach B. A comparison between 915 MHz and 2450 MHz microwave ablation systems for the treatment of small diameter lung metastases. Diagnostic and Interventional Radiology. 2018;24(1):31–37. Ineligible population29317376
110 Voynov G, Heron DE, Lin CJ, Intraoperative 125I Vicryl mesh brachytherapy after sublobar resection for high-risk stage I nonsmall cell lung cancer. Brachytherapy. 2005;4(4):278–285. Ineligible intervention16344258
111 Zaric B, Canak V, Milovancev A, The effect of Nd:YAG laser resection on symptom control, time to progression and survival in lung cancer patients. Journal of BUON. 2007;12(3):361–368. Ineligible intervention17918290
112 Zhang Z, Mao H, Wang X, Sheng W. Comparison of I125seed brachytherapy (radioactive seed brachytherapy) joint three-dimensional conformal radiotherapy and stereotactic ablative radiotherapy on early nonsmall cell lung cancer. Journal of Cancer Research and Therapeutics. 2020;16(7):1560–1568. Ineligible population33565500