# APPENDIX A SEARCH STRATEGIES

## MEDLINE & EMBASE

### Key Question 1&2

| Search Terms
1 | Exp lung neoplasms/di, rt, su, th [diagnosis, radiotherapy, surgery, therapy]
2 | Non-small-cell lung carcinomas.tw
3 | Non-small cell lung cancer.tw
4 | Nsclc.tw
5 | OR/1-4
6 | Radiation Dose Hypofractionation/ or (radiotherapy minibeam$1 or radiation hypofractionated dose or radiation dose hypofractionation or hypofractionated radiation therapy or short?course radiation therapy).ti,ab.
7 | dose fractionation/ or dose response relationship, radiation/ or radiotherapy dosage/
8 | ((radiotherapy* or radiat*) adj2 (dose or dosage or regimen* or schedule*)).tw.
9 | hypofractionat*.mp.
10 | hypo-fraction*.mp.
11 | multi-fraction*.tw.
12 | (hypo adj3 fraction*).tw.
13 | Stereotactic body radiation therapy/ or SBRT.mp.
14 | Stereotactic ablative body radiation therapy/ or SABR.mp.
15 | (Stereotactic body radiation therapy or SBRT).tw.
16 | (Stereotactic ablative body radiation therapy or SABR).tw.
17 | Exp radiosurgery/
18 | Or/6-17
19 | Lung cancer terms and SBRT (5 and 18)
20 | (thoracic surg*).tw,kw.
21 | Lobectomy.tw
22 | Video-assisted thoracoscopic surgery.tw
23 | VATS.tw
24 | Posterolateral thoracotomy.tw
25 | Sublobar resection.tw
26 | Segmentectomy.tw
27 | Sublobectom or wedge resection.tw
28 | Segmental resection.tw
29 | Limited resection.tw
30 | Or/20-29
31 | Lung cancer terms and Surgery (5 and 30)
32 | Randomized controlled trial.pt. or randomized.mp. or placebo.mp.
33 | Randomized controlled trial/ or random allocation/ or double-blind method/ or single-blind method/ or placebos/
34 | (‘clinical trial’ or ‘randomized controlled study’ or ‘randomized controlled trial’ or ‘double blind clinical study’ or ‘single blind clinical study’ or ‘random allocation’).ti,ab.
35 | Or/32-34
36 | 19 or 31
37 | 35 and 36
38 | Limit 37 to English language
39 | Limit 38 to yr=”2000-current”

### Key Question 3

| Search Terms
1 | Exp lung neoplasms/di, rt, su, th [diagnosis, radiotherapy, surgery, therapy]
2 | Non-small-cell lung carcinomas.tw
3 | Non-small cell lung cancer.tw
4 | Nsclc.tw
5 | OR/1-4
6 | exp cryosurgery/
7 | exp Radiofrequency Therapy/
8 | (((radiofrequency or microwave) adj1 ablation) or brachytherapy).tw.
9 | Exp brachytherapy/
10 | (Microwaves exp Mesh Term/ OR microwaves.tw OR “Radio Waves” exp Mesh Term/ or Radiowaves.tw or “radio waves”.tw) OR ((“Radiowaves”.tw OR “Radio Waves”.tw) AND “ablation”.tw)
11 | (Cryoabalation.tw OR Cryoprobes.tw OR Cryotherapy Mesh Term/ OR Cryotherapy.tw OR Cryosurgery.tw OR Cryogen*.tw)
12 | Or/6-11
13 | Lung cancer with other treatment (5 and 12)
14 | Limit 13 to English language
15 | Limit 14 to yr = “2000-current”

## AHRQ, COCHRANE, VA ESP KEYWORDS

Lung cancer, lung malignancy, malignant, lung, radiotherapy, ablative therapy