# ABBREVIATIONS TABLE

Abbreviation
AHRQ: Agency for Healthcare Research and Quality
AJCC: American Joint Commission on Cancer
ARD: Adjusted risk difference
BAC: Bronchioloalveolar carcinoma
BED: Biologically effective dose
CBO: Centraal Begeleidingsorgaan voorde Intercollegiale Toetsing (Dutch Institute for Healthcare Improvement)
CI: Confidence interval
CT: Computed tomography
CVA: Cerebral vascular accident
ECOG: Eastern Cooperative Oncology Group
EORTC QLQ-C30: The 30-item European Organization for Research and Treatment of Cancer Quality of Life Core questionnaire
EQ-5D: The EuroQoL disease-specific questionnaire
ESP: Evidence Synthesis Program
FEV: Fluorodeoxyglucose-positron emission tomography
GDT: Guideline Development Tool
GRADE: Grading of Recommendation, Assessment, Development, and Evaluation
Gy: Gray
HR: Hazard ratio
IASCL: International Association for the Study of Lung Cancer
IQR: Interquartile range
KQ: Key question
L: Left
LC-13: The 13-item lung cancer supplement to the EORTC QLQ-C30
MI: Myocardial infarction
MWA: Microwave ablation
NA: Not available
NCDB: National Cancer Database
NR: Not reported
NSCLC: Non-small cell lung cancer
PET: Positron emission tomography
PRISMA: Preferred Reporting Items for Systematic Reviews and Meta-Analyses
PROSPERO: International Prospective Register of Systematic Reviews
QoL: Quality of life
R: Right
RCT: Randomized controlled trial
RFA: Radiofrequency ablation
RoB: Risk of bias
ROSEL: Trial of Either Surgery or Stereotactic Radiotherapy for Early Stage (IA) Lung Cancer
RR: Risk ratio
SABR: Stereotactic ablative radiotherapy
SBRT: Stereotactic body radiation therapy
SD: Standard deviation
SEER: Surveillance, Epidemiology and End-Results database
STARS: Randomized Study to Compare CyberKnife to Surgical Resection in Stage I Non-Small Cell Lung Cancer
TEP: Technical expert panel
TNM: Tumor, node,metastasis
US/USA: United States of America
USPSTF: US Preventative Services Task Force
VA: Veterans Health Administration
VALOR: Veterans Affairs Lung Cancer Surgery Or Stereotactic Radiotherapy trial
VATB: Video-assisted thoracotomy biopsy
VATL: Video-assisted thoracotomy lobectomy
VATS: Video-assisted thorascopic surgery
VATS L-MLND: Video-assisted thorascopic surgical lobectomy with mediastinal lymph node dissection