# REFERENCES

1 Trivedi RB, Post EP, Sun H, . Prevalence, Comorbidity, and Prognosis of Mental Health Among US Veterans. Am J Public Health. 2015;105(12):2564–2569.26474009
2 Seal KH, Metzler TJ, Gima KS, Bertenthal D, Maguen S, Marmar CR. Trends and risk factors for mental health diagnoses among Iraq and Afghanistan veterans using Department of Veterans Affairs health care, 2002-2008. Am J Public Health. 2009;99(9):1651–1658.19608954
3 In: Treatment for Posttraumatic Stress Disorder in Military and Veteran Populations: Final Assessment. Washington (DC) 2014.
4 Kessler RC, Bromet EJ. The epidemiology of depression across cultures. Annu Rev Public Health. 2013;34:119–138.23514317
5 World Health Organization. Depression and other common mental disorders. https://www.who.int/publications/i/item/depression-global-health-estimates. Published 2017. Accessed September 12, 2022.
6 Zhdanava M, Pilon D, Ghelerter I, . The Prevalence and National Burden of Treatment-Resistant Depression and Major Depressive Disorder in the United States. J Clin Psychiatry. 2021;82(2).
7 Department of Veterans Affairs. FY 2023 Budget Submission for Medical Programs and Information Technology Programs. https://www.va.gov/budget/docs/summary/fy2023-va-budget-volume-ii-medical-programs-and-information-technology.pdf. Published 2022. Accessed September12, 2022.
8 Stein MB, Levey DF, Cheng Z, . Genome-wide association analyses of post-traumatic stress disorder and its symptom subdomains in the Million Veteran Program. Nat Genet. 2021;53(2):174–184.33510476
9 Department of Veterans Affairs. Million Veteran Program. https://www.mvp.va.gov/pwa/. Accessed September 12, 2022.
10 Bode AM, Dong Z. Recent advances in precision oncology research. NPJ Precis Oncol. 2018;2:11.30202789
11 Nadauld LD, Ford JM, Pritchard D, Brown T. Strategies For Clinical Implementation: Precision Oncology At Three Distinct Institutions. Health Aff (Millwood). 2018;37(5):751–756.29733728
12 Fernandes BS, Williams LM, Steiner J, Leboyer M, Carvalho AF, Berk M. The new field of ‘precision psychiatry’. BMC Med. 2017;15(1):80.28403846
13 Williams LM. Precision psychiatry: a neural circuit taxonomy for depression and anxiety. Lancet Psychiatry. 2016;3(5):472–480.27150382
14 Benkarim O, Paquola C, Park BY, . Population heterogeneity in clinical cohorts affects the predictive accuracy of brain imaging. PLoS Biol. 2022;20(4):e3001627.35486643
15 Marek S, Tervo-Clemmens B, Calabro FJ, . Reproducible brain-wide association studies require thousands of individuals. Nature. 2022;603(7902):654–660.35296861
16 Specht K. Current Challenges in Translational and Clinical fMRI and Future Directions. Front Psychiatry. 2019;10:924.31969840
17 White T, Blok E, Calhoun VD. Data sharing and privacy issues in neuroimaging research: Opportunities, obstacles, challenges, and monsters under the bed. Hum Brain Mapp. 2022;43(1):278–291.32621651
18 Bethlehem RAI, Seidlitz J, White SR, . Brain charts for the human lifespan. Nature. 2022;604(7906):525–533.35388223
19 Commander John Scott Hannon Veterans Mental Health Care Improvement Act of 2019. https://www.govinfo.gov/content/pkg/PLAW-116publ171/pdf/PLAW-116publ171.pdf. Accessed September 12, 2022.
20 Bragge P, Clavisi O, Turner T, Tavender E, Collie A, Gruen RL. The Global Evidence Mapping Initiative: scoping research in broad topic areas. BMC Med Res Methodol. 2011;11:92.21682870
21 Miake-Lye IM, Hempel S, Shanman R, Shekelle PG. What is an evidence map? A systematic review of published evidence maps and their definitions, methods, and products. Syst Rev. 2016;5:28.26864942
22 Runia N, Yucel DE, Lok A, . The neurobiology of treatment-resistant depression: A systematic review of neuroimaging studies. Neurosci Biobehav Rev. 2022;132:433–448.34890601
23 Karim HT, Wang M, Andreescu C, . Acute trajectories of neural activation predict remission to pharmacotherapy in late-life depression. Neuroimage Clin. 2018;19:831–839.30013927
24 Lebedeva AK, Westman E, Borza T, . MRI-Based Classification Models in Prediction of Mild Cognitive Impairment and Dementia in Late-Life Depression. Front Aging Neurosci. 2017;9:13.28210220
25 Patel MJ, Andreescu C, Price JC, Edelman KL, Reynolds CF, 3rd, Aizenstein HJ. Machine learning approaches for integrating clinical and imaging features in late-life depression classification and response prediction. Int J Geriatr Psychiatry. 2015;30(10):1056–1067.25689482
26 Taylor WD, McQuoid DR, Payne ME, Zannas AS, MacFall JR, Steffens DC. Hippocampus atrophy and the longitudinal course of late-life depression. Am J Geriatr Psychiatry. 2014;22(12):1504–1512.24378256
27 Niida A, Niida R, Matsuda H, Inada T, Motomura M, Uechi A. Identification of atrophy of the subgenual anterior cingulate cortex, in particular the subcallosal area, as an effective auxiliary means of diagnosis for major depressive disorder. Int J Gen Med. 2012;5:667–674.22924012
28 Bi K, Luo G, Tian S, . An enriched granger causal model allowing variable static anatomical constraints. Neuroimage Clin. 2019;21:101592.30448217
29 Deng F, Wang Y, Huang H, . Abnormal segments of right uncinate fasciculus and left anterior thalamic radiation in major and bipolar depression. Prog Neuropsychopharmacol Biol Psychiatry. 2018;81:340–349.28912043
30 Schnyer DM, Clasen PC, Gonzalez C, Beevers CG. Evaluating the diagnostic utility of applying a machine learning algorithm to diffusion tensor MRI measures in individuals with major depressive disorder. Psychiatry Res Neuroimaging. 2017;264:1–9.28388468
31 Bi K, Hua L, Wei M, Qin J, Lu Q, Yao Z. Dynamic functional-structural coupling within acute functional state change phases: Evidence from a depression recognition study. J Affect Disord. 2016;191:145–155.26655124
32 Korgaonkar MS, Cooper NJ, Williams LM, Grieve SM. Mapping inter-regional connectivity of the entire cortex to characterize major depressive disorder: a whole-brain diffusion tensor imaging tractography study. Neuroreport. 2012;23(9):566–571.22562047
33 He Z, Sheng W, Lu F, . Altered resting-state cerebral blood flow and functional connectivity of striatum in bipolar disorder and major depressive disorder. Prog Neuropsychopharmacol Biol Psychiatry. 2019;90:177–185.30500413
34 Almeida JR, Mourao-Miranda J, Aizenstein HJ, . Pattern recognition analysis of anterior cingulate cortex blood flow to classify depression polarity. Br J Psychiatry. 2013;203(3):310–311.23969484
35 Schmaal L, Marquand AF, Rhebergen D, . Predicting the Naturalistic Course of Major Depressive Disorder Using Clinical and Multimodal Neuroimaging Information: A Multivariate Pattern Recognition Study. Biol Psychiatry. 2015;78(4):278–286.25702259
36 Braund TA, Breukelaar IA, Griffiths K, . Intrinsic Functional Connectomes Characterize Neuroticism in Major Depressive Disorder and Predict Antidepressant Treatment Outcomes. Biol Psychiatry Cogn Neurosci Neuroimaging. 2022;7(3):276–284.34363999
37 Korgaonkar MS, Goldstein-Piekarski AN, Fornito A, Williams LM. Intrinsic connectomes are a predictive biomarker of remission in major depressive disorder. Mol Psychiatry. 2020;25(7):1537–1549.31695168
38 Gyurak A, Patenaude B, Korgaonkar MS, Grieve SM, Williams LM, Etkin A. Frontoparietal Activation During Response Inhibition Predicts Remission to Antidepressants in Patients With Major Depression. Biol Psychiatry. 2016;79(4):274–281.25891220
39 Williams LM, Korgaonkar MS, Song YC, . Amygdala Reactivity to Emotional Faces in the Prediction of General and Medication-Specific Responses to Antidepressant Treatment in the Randomized iSPOT-D Trial. Neuropsychopharmacology. 2015;40(10):2398–2408.25824424
40 Grieve SM, Korgaonkar MS, Etkin A, . Brain imaging predictors and the international study to predict optimized treatment for depression: study protocol for a randomized controlled trial. Trials. 2013;14:224.23866851
41 Drysdale AT, Grosenick L, Downar J, . Resting-state connectivity biomarkers define neurophysiological subtypes of depression. Nat Med. 2017;23(1):28–38.27918562
42 Zhang Y, Kong Y, Liu X, . Desynchronized Functional Activities Between Brain White and Gray Matter in Major Depression Disorder. J Magn Reson Imaging. 2021;53(5):1375–1386.33305508
43 Tian S, Sun Y, Shao J, . Predicting escitalopram monotherapy response in depression: The role of anterior cingulate cortex. Hum Brain Mapp. 2020;41(5):1249–1260.31758634
44 Liu S, Liu X, Yan D, . Alterations in Patients With First-Episode Depression in the Eyes-Open and Eyes-Closed Conditions: A Resting-State EEG Study. IEEE Trans Neural Syst Rehabil Eng. 2022;30:1019–1029.35412986
45 Li X, La R, Wang Y, . EEG-based mild depression recognition using convolutional neural network. Med Biol Eng Comput. 2019;57(6):1341–1352.30778842
46 Wu CT, Huang HC, Huang S, . Resting-State EEG Signal for Major Depressive Disorder Detection: A Systematic Validation on a Large and Diverse Dataset. Biosensors (Basel). 2021;11(12).
47 Shim M, Jin MJ, Im CH, Lee SH. Machine-learning-based classification between post-traumatic stress disorder and major depressive disorder using P300 features. Neuroimage Clin. 2019;24:102001.31627171
48 Ding X, Yue X, Zheng R, Bi C, Li D, Yao G. Classifying major depression patients and healthy controls using EEG, eye tracking and galvanic skin response data. J Affect Disord. 2019;251:156–161.30925266
49 Fan X, Huang X, Zhao Y, Wang L, Yu H, Zhao G. Predicting Prognostic Effects of Acupuncture for Depression Using the Electroencephalogram. Evid Based Complement Alternat Med. 2022;2022:1381683.35280515
50 Zehong C, Chin-Teng L, Weiping D, Mu-Hong C, Cheng-Ta L, Tung-Ping S. Identifying Ketamine Responses in Treatment-Resistant Depression Using a Wearable Forehead EEG. IEEE Trans Biomed Eng. 2019;66(6):1668–1679.30369433
51 Isserles M, Daskalakis ZJ, George MS, Blumberger DM, Sackeim HA, Shahaf G. Simple Electroencephalographic Treatment-Emergent Marker Can Predict Repetitive Transcranial Magnetic Stimulation Antidepressant Response-A Feasibility Study. J ECT. 2018;34(4):274–282.30407932
52 Jaworska N, de la Salle S, Ibrahim MH, Blier P, Knott V. Leveraging Machine Learning Approaches for Predicting Antidepressant Treatment Response Using Electroencephalography (EEG) and Clinical Data. Front Psychiatry. 2018;9:768.30692945
53 Li CT, Hsieh JC, Huang HH, . Cognition-Modulated Frontal Activity in Prediction and Augmentation of Antidepressant Efficacy: A Randomized Controlled Pilot Study. Cereb Cortex. 2016;26(1):202–210.25165064
54 Cook IA, Hunter AM, Gilmer WS, . Quantitative electroencephalogram biomarkers for predicting likelihood and speed of achieving sustained remission in major depression: a report from the biomarkers for rapid identification of treatment effectiveness in major depression (BRITE-MD) trial. J Clin Psychiatry. 2013;74(1):51–56.23419226
55 Wang Q, Tian S, Zhao P, Cao Q, Lu Q, Yao Z. Association Between Antidepressant Efficacy and Interactions of Three Core Depression-Related Brain Networks in Major Depressive Disorder. Front Psychiatry. 2022;13:862507.35356714
56 Liu TY, Chen YS, Su TP, Hsieh JC, Chen LF. Abnormal early gamma responses to emotional faces differentiate unipolar from bipolar disorder patients. Biomed Res Int. 2014;2014:906104.24738077
57 Wang Q, Tian S, Tang H, . Identification of major depressive disorder and prediction of treatment response using functional connectivity between the prefrontal cortices and subgenual anterior cingulate: A real-world study. J Affect Disord. 2019;252:365–372.30999093
58 Pillai RL, Zhang M, Yang J, . Molecular connectivity disruptions in males with major depressive disorder. J Cereb Blood Flow Metab. 2019;39(8):1623–1634.29519187
59 Kaufman J, Sullivan GM, Yang J, . Quantification of the Serotonin 1A Receptor Using PET: Identification of a Potential Biomarker of Major Depression in Males. Neuropsychopharmacology. 2015;40(7):1692–1699.25578798
60 Yeh YW, Ho PS, Kuo SC, . Disproportionate Reduction of Serotonin Transporter May Predict the Response and Adherence to Antidepressants in Patients with Major Depressive Disorder: A Positron Emission Tomography Study with 4-[18F]-ADAM. Int J Neuropsychopharmacol. 2015;18(7):pyu120.25568284
61 Amen DG, Krishnamani P, Meysami S, Newberg A, Raji CA. Classification of Depression, Cognitive Disorders, and Co-Morbid Depression and Cognitive Disorders with Perfusion SPECT Neuroimaging. J Alzheimers Dis. 2017;57(1):253–266.28211813
62 Richieri R, Verger A, Boyer L, . Predictive value of dorso-lateral prefrontal connectivity for rTMS response in treatment-resistant depression: A brain perfusion SPECT study. Brain Stimul. 2018;11(5):1093–1097.29802071
63 Richieri R, Boyer L, Farisse J, . Predictive value of brain perfusion SPECT for rTMS response in pharmacoresistant depression. Eur J Nucl Med Mol Imaging. 2011;38(9):1715–1722.21647787
64 Tekin Erguzel T, Tas C, Cebi M. A wrapper-based approach for feature selection and classification of major depressive disorder-bipolar disorders. Comput Biol Med. 2015;64:127–137.26164033
65 Schnack HG, Nieuwenhuis M, van Haren NE, . Can structural MRI aid in clinical classification? A machine learning study in two independent samples of patients with schizophrenia, bipolar disorder and healthy subjects. Neuroimage. 2014;84:299–306.24004694
66 Mwangi B, Wu MJ, Cao B, . Individualized Prediction and Clinical Staging of Bipolar Disorders using Neuroanatomical Biomarkers. Biol Psychiatry Cogn Neurosci Neuroimaging. 2016;1(2):186–194.27047994
67 Yang T, Frangou S, Lam RW, . Probing the clinical and brain structural boundaries of bipolar and major depressive disorder. Transl Psychiatry. 2021;11(1):48.33446647
68 Niida R, Yamagata B, Niida A, Uechi A, Matsuda H, Mimura M. Aberrant Anterior Thalamic Radiation Structure in Bipolar Disorder: A Diffusion Tensor Tractography Study. Front Psychiatry. 2018;9:522.30405460
69 Frangou S, Dima D, Jogia J. Towards person-centered neuroimaging markers for resilience and vulnerability in Bipolar Disorder. Neuroimage. 2017;145(Pt B):230–237.27622393
70 Shi J, Geng J, Yan R, . Differentiation of Transformed Bipolar Disorder From Unipolar Depression by Resting-State Functional Connectivity Within Reward Circuit. Front Psychol. 2018;9:2586.30622492
71 Serpa MH, Ou Y, Schaufelberger MS, . Neuroanatomical classification in a population-based sample of psychotic major depression and bipolar I disorder with 1 year of diagnostic stability. Biomed Res Int. 2014;2014:706157.24575411
72 Tsolaki E, Narr KL, Espinoza R, . Subcallosal Cingulate Structural Connectivity Differs in Responders and Nonresponders to Electroconvulsive Therapy. Biol Psychiatry Cogn Neurosci Neuroimaging. 2021;6(1):10–19.32741703
73 Sun H, Jiang R, Qi S, . Preliminary prediction of individual response to electroconvulsive therapy using whole-brain functional magnetic resonance imaging data. Neuroimage Clin. 2020;26:102080.31735637
74 Wade BS, Joshi SH, Njau S, . Effect of Electroconvulsive Therapy on Striatal Morphometry in Major Depressive Disorder. Neuropsychopharmacology. 2016;41(10):2481–2491.27067127
75 Bruin WB, Oltedal L, Bartsch H, . Development and validation of a multimodal neuroimaging biomarker for electroconvulsive therapy outcome in depression: a multicenter machine learning analysis. medRxiv. 2022.
76 Lanka P, Rangaprakash D, Dretsch MN, Katz JS, Denney TS, Jr., Deshpande G. Supervised machine learning for diagnostic classification from large-scale neuroimaging datasets. Brain Imaging Behav. 2020;14(6):2378–2416.31691160
77 Zhang J, Richardson JD, Dunkley BT. Classifying post-traumatic stress disorder using the magnetoencephalographic connectome and machine learning. Sci Rep. 2020;10(1):5937.32246035
78 Suo X, Lei D, Li W, . Individualized Prediction of PTSD Symptom Severity in Trauma Survivors From Whole-Brain Resting-State Functional Connectivity. Front Behav Neurosci. 2020;14:563152.33408617
79 Im JJ, Kim B, Hwang J, . Diagnostic potential of multimodal neuroimaging in posttraumatic stress disorder. PLoS One. 2017;12(5):e0177847.28558004
80 Zhutovsky P, Thomas RM, Olff M, . Individual prediction of psychotherapy outcome in posttraumatic stress disorder using neuroimaging data. Transl Psychiatry. 2019;9(1):326.31792202
81 van Rooij SJ, Kennis M, Vink M, Geuze E. Predicting Treatment Outcome in PTSD: A Longitudinal Functional MRI Study on Trauma-Unrelated Emotional Processing. Neuropsychopharmacology. 2016;41(4):1156–1165.26289143
82 Stout DM, Harle KM, Norman SB, Simmons AN, Spadoni AD. Resting-state connectivity subtype of comorbid PTSD and alcohol use disorder moderates improvement from integrated prolonged exposure therapy in Veterans. Psychol Med. 2021:1–10.
83 Klumpp H, Jimmy J, Burkhouse KL, . Brain response to emotional faces in anxiety and depression: neural predictors of cognitive behavioral therapy outcome and predictor-based subgroups following therapy. Psychol Med. 2020:1–11.
84 Etkin A, Maron-Katz A, Wu W, . Using fMRI connectivity to define a treatment-resistant form of post-traumatic stress disorder. Sci Transl Med. 2019;11(486).
85 Fonzo GA, Goodkind MS, Oathes DJ, . PTSD Psychotherapy Outcome Predicted by Brain Activation During Emotional Reactivity and Regulation. Am J Psychiatry. 2017;174(12):1163–1174.28715908
86 Laxminarayan S, Wang C, Oyama T, Cashmere JD, Germain A, Reifman J. Identification of Veterans With PTSD Based on EEG Features Collected During Sleep. Front Psychiatry. 2020;11:532623.33329079
87 Kim YW, Kim S, Shim M, . Riemannian classifier enhances the accuracy of machine-learning-based diagnosis of PTSD using resting EEG. Prog Neuropsychopharmacol Biol Psychiatry. 2020;102:109960.32376342
88 Tahmasian M, Jamalabadi H, Abedini M, . Differentiation chronic post traumatic stress disorder patients from healthy subjects using objective and subjective sleep-related parameters. Neurosci Lett. 2017;650:174–179.28450190
89 Shu IW, Onton JA, O’Connell RM, Simmons AN, Matthews SC. Combat veterans with comorbid PTSD and mild TBI exhibit a greater inhibitory processing ERP from the dorsal anterior cingulate cortex. Psychiatry Res. 2014;224(1):58–66.25150386
90 James LM, Leuthold AF, Georgopoulos AP. Classification of posttraumatic stress disorder and related outcomes in women veterans using magnetoencephalography. Exp Brain Res. 2022;240(4):1117–1125.35133447
91 Georgopoulos AP, Tan HR, Lewis SM, . The synchronous neural interactions test as a functional neuromarker for post-traumatic stress disorder (PTSD): a robust classification method based on the bootstrap. J Neural Eng. 2010;7(1):16011.20086271
92 Amen DG, Raji CA, Willeumier K, . Functional Neuroimaging Distinguishes Posttraumatic Stress Disorder from Traumatic Brain Injury in Focused and Large Community Datasets. PLoS One. 2015;10(7):e0129659.26132293
93 Raji CA, Willeumier K, Taylor D, . Functional neuroimaging with default mode network regions distinguishes PTSD from TBI in a military veteran population. Brain Imaging Behav. 2015;9(3):527–534.25917871
94 Neumeister A, Normandin MD, Pietrzak RH, . Elevated brain cannabinoid CB1 receptor availability in post-traumatic stress disorder: a positron emission tomography study. Mol Psychiatry. 2013;18(9):1034–1040.23670490
95 Rangaprakash D, Dretsch MN, Venkataraman A, Katz JS, Denney TS, Jr., Deshpande G. Identifying disease foci from static and dynamic effective connectivity networks: Illustration in soldiers with trauma. Hum Brain Mapp. 2018;39(1):264–287.29058357
96 Rangaprakash D, Deshpande G, Daniel TA, . Compromised hippocampus-striatum pathway as a potential imaging biomarker of mild-traumatic brain injury and posttraumatic stress disorder. Hum Brain Mapp. 2017;38(6):2843–2864.28295837
97 Rangaprakash D, Dretsch MN, Katz JS, Denney TS, Jr., Deshpande G. Dynamics of Segregation and Integration in Directional Brain Networks: Illustration in Soldiers With PTSD and Neurotrauma. Front Neurosci. 2019;13:803.31507353
98 Hanks R, Millis S, Scott S, . The relation between cognitive dysfunction and diffusion tensor imaging parameters in traumatic brain injury. Brain Inj. 2019;33(3):355–363.30563361
99 Huang M, Lee RR. Magnetoencephalography (MEG) Slow-Wave Imaging for Diagnosing Non-acute Mild Traumatic Brain Injury. Current Radiology Reports. 2015;3(10):41.
100 Main KL, Soman S, Pestilli F, . DTI measures identify mild and moderate TBI cases among patients with complex health problems: A receiver operating characteristic analysis of U.S. veterans. Neuroimage Clin. 2017;16:1–16.28725550
101 Chen YC, Chen YL, Kuo DP, . Personalized Prediction of Postconcussive Working Memory Decline: A Feasibility Study. J Pers Med. 2022;12(2).
102 Brezova V, Moen KG, Skandsen T, . Prospective longitudinal MRI study of brain volumes and diffusion changes during the first year after moderate to severe traumatic brain injury. Neuroimage Clin. 2014;5:128–140.25068105
103 McBride J, Zhao X, Nichols T, . Scalp EEG-based discrimination of cognitive deficits after traumatic brain injury using event-related Tsallis entropy analysis. IEEE Trans Biomed Eng. 2013;60(1):90–96.23070292
104 Camchong J, Haynos AF, Hendrickson T, . Resting Hypoconnectivity of Theoretically Defined Addiction Networks during Early Abstinence Predicts Subsequent Relapse in Alcohol Use Disorder. Cereb Cortex. 2022;32(12):2688–2702.34671808
105 Dai X, Gao L, Zhang H, Wei X, Liu Z. A combination of support vector machine and voxel-based morphometry in adult male alcohol use disorder patients with cognitive deficits. Brain Res. 2021;1771:147644.34478708
106 Kamarajan C, Ardekani BA, Pandey AK, . Random Forest Classification of Alcohol Use Disorder Using EEG Source Functional Connectivity, Neuropsychological Functioning, and Impulsivity Measures. Behav Sci (Basel). 2020;10(3).
107 Kinreich S, McCutcheon VV, Aliev F, . Predicting alcohol use disorder remission: a longitudinal multimodal multi-featured machine learning approach. Transl Psychiatry. 2021;11(1):166.33723218
108 Mishra P, Nizamie SH, Jahan M, . Predictors of chronicity in alcohol use disorder: an evoked response potential study. J Addict Dis. 2020;38(4):411–419.32602787
109 Sekutowicz M, Guggenmos M, Kuitunen-Paul S, . Neural Response Patterns During Pavlovian-to-Instrumental Transfer Predict Alcohol Relapse and Young Adult Drinking. Biol Psychiatry. 2019;86(11):857–863.31521335
110 Mumtaz W, Saad M, Kamel N, Ali SSA, Malik AS. An EEG-based functional connectivity measure for automatic detection of alcohol use disorder. Artif Intell Med. 2018;84:79–89.29169647
111 Durazzo TC, Meyerhoff DJ. Psychiatric, Demographic, and Brain Morphological Predictors of Relapse After Treatment for an Alcohol Use Disorder. Alcohol Clin Exp Res. 2017;41(1):107–116.27883214
112 Mumtaz W, Vuong PL, Xia L, Malik AS, Rashid RBA. An EEG-based machine learning method to screen alcohol use disorder. Cogn Neurodyn. 2017;11(2):161–171.28348647
113 Januszko P, Gmaj B, Piotrowski T, . Delta resting-state functional connectivity in the cognitive control network as a prognostic factor for maintaining abstinence: An eLORETA preliminary study. Drug Alcohol Depend. 2021;218:108393.33158664
114 Zhu X, Du X, Kerich M, Lohoff FW, Momenan R. Random forest based classification of alcohol dependence patients and healthy controls using resting state MRI. Neurosci Lett. 2018;676:27–33.29626649
115 Zhai T, Gu H, Yang Y. Cox Regression Based Modeling of Functional Connectivity and Treatment Outcome for Relapse Prediction and Disease Subtyping in Substance Use Disorder. Front Neurosci. 2021;15:768602.34858131
116 McHugh MJ, Demers CH, Salmeron BJ, Devous MD, Sr., Stein EA, Adinoff B. Cortico-amygdala coupling as a marker of early relapse risk in cocaine-addicted individuals. Front Psychiatry. 2014;5:16.24578695
117 Adinoff B, Gu H, Merrick C, . Basal Hippocampal Activity and Its Functional Connectivity Predicts Cocaine Relapse. Biol Psychiatry. 2015;78(7):496–504.25749098
118 Erguzel TT, Uyulan C, Unsalver B, . Entropy: A Promising EEG Biomarker Dichotomizing Subjects With Opioid Use Disorder and Healthy Controls. Clin EEG Neurosci. 2020;51(6):373–381.32043373
119 Erguzel TT, Noyan CO, Eryilmaz G, . Binomial Logistic Regression and Artificial Neural Network Methods to Classify Opioid-Dependent Subjects and Control Group Using Quantitative EEG Power Measures. Clin EEG Neurosci. 2019;50(5):303–310.30642219
120 Yan C, Yang X, Yang R, . Treatment Response Prediction and Individualized Identification of Short-Term Abstinence Methamphetamine Dependence Using Brain Graph Metrics. Front Psychiatry. 2021;12:583950.33746790
121 Li Y, Cui Z, Liao Q, . Support vector machine-based multivariate pattern classification of methamphetamine dependence using arterial spin labeling. Addict Biol. 2019;24(6):1254–1262.30623517
122 Gowin JL, Ball TM, Wittmann M, Tapert SF, Paulus MP. Individualized relapse prediction: Personality measures and striatal and insular activity during reward-processing robustly predict relapse. Drug Alcohol Depend. 2015;152:93–101.25977206
123 Chen Y, Ou Y, Lv D, . Decreased Nucleus Accumbens Connectivity at Rest in Medication-Free Patients with Obsessive-Compulsive Disorder. Neural Plast. 2021;2021:9966378.34158811
124 Liu W, Qin J, Tang Q, . Disrupted pathways from the frontal-parietal cortices to basal nuclei and the cerebellum are a feature of the obsessive-compulsive disorder spectrum and can be used to aid in early differential diagnosis. Psychiatry Res. 2020;293:113436.32889343
125 Zhou C, Cheng Y, Ping L, . Support Vector Machine Classification of Obsessive-Compulsive Disorder Based on Whole-Brain Volumetry and Diffusion Tensor Imaging. Front Psychiatry. 2018;9:524.30405461
126 Hu X, Liu Q, Li B, . Multivariate pattern analysis of obsessive-compulsive disorder using structural neuroanatomy. Eur Neuropsychopharmacol. 2016;26(2):246–254.26708318
127 Liu J, Bu X, Hu X, . Temporal variability of regional intrinsic neural activity in drug-naive patients with obsessive-compulsive disorder. Hum Brain Mapp. 2021;42(12):3792–3803.33949731
128 Lv D, Ou Y, Wang Y, . Altered Functional Connectivity Strength at Rest in Medication-Free Obsessive-Compulsive Disorder. Neural Plast. 2021;2021:3741104.34539777
129 Yang P, Zhao C, Yang Q, . Diagnosis of obsessive-compulsive disorder via spatial similarity-aware learning and fused deep polynomial network. Med Image Anal. 2022;75:102244.34700244
130 Luo Q, Liu W, Jin L, Chang C, Peng Z. Classification of Obsessive-Compulsive Disorder Using Distance Correlation on Resting-State Functional MRI Images. Front Neuroinform. 2021;15:676491.34744676
131 Liu W, Hua M, Qin J, . Disrupted pathways from frontal-parietal cortex to basal ganglia and cerebellum in patients with unmedicated obsessive compulsive disorder as observed by whole-brain resting-state effective connectivity analysis - a small sample pilot study. Brain Imaging Behav. 2021;15(3):1344–1354.32743721
132 Kwak S, Kim M, Kim T, . Defining data-driven subgroups of obsessive-compulsive disorder with different treatment responses based on resting-state functional connectivity. Transl Psychiatry. 2020;10(1):359.33106472
133 Wang YM, Cai XL, Zhang RT, . Searchlight classification based on Amplitude of Low Frequency Fluctuation and functional connectivity in individuals with obsessive-compulsive symptoms. Cogn Neuropsychiatry. 2019;24(5):322–334.31451062
134 Yang X, Hu X, Tang W, . Multivariate classification of drug-naive obsessive-compulsive disorder patients and healthy controls by applying an SVM to resting-state functional MRI data. BMC Psychiatry. 2019;19(1):210.31277632
135 Takagi Y, Sakai Y, Lisi G, . A Neural Marker of Obsessive-Compulsive Disorder from Whole-Brain Functional Connectivity. Sci Rep. 2017;7(1):7538.28790433
136 Hu X, Zhang L, Bu X, . Localized Connectivity in Obsessive-Compulsive Disorder: An Investigation Combining Univariate and Multivariate Pattern Analyses. Front Behav Neurosci. 2019;13:122.31249515
137 Cui G, Ou Y, Chen Y, . Altered Global Brain Functional Connectivity in Drug-Naive Patients With Obsessive-Compulsive Disorder. Front Psychiatry. 2020;11:98.32194450
138 Li F, Huang X, Tang W, . Multivariate pattern analysis of DTI reveals differential white matter in individuals with obsessive-compulsive disorder. Hum Brain Mapp. 2014;35(6):2643–2651.24048702
139 Altuglu TB, Metin B, Tulay EE, . Prediction of treatment resistance in obsessive compulsive disorder patients based on EEG complexity as a biomarker. Clin Neurophysiol. 2020;131(3):716–724.32000072
140 Yun JY, Jang JH, Kim SN, Jung WH, Kwon JS. Neural Correlates of Response to Pharmacotherapy in Obsessive-Compulsive Disorder: Individualized Cortical Morphology-Based Structural Covariance. Prog Neuropsychopharmacol Biol Psychiatry. 2015;63:126–133.26116795
141 Reggente N, Moody TD, Morfini F, . Multivariate resting-state functional connectivity predicts response to cognitive behavioral therapy in obsessive-compulsive disorder. Proc Natl Acad Sci U S A. 2018;115(9):2222–2227.29440404
142 Liu F, Guo W, Fouche JP, . Multivariate classification of social anxiety disorder using whole brain functional connectivity. Brain Struct Funct. 2015;220(1):101–115.24072164
143 Xing M, Fitzgerald JM, Klumpp H. Classification of Social Anxiety Disorder With Support Vector Machine Analysis Using Neural Correlates of Social Signals of Threat. Front Psychiatry. 2020;11:144.32231598
144 Qiao J, Li A, Cao C, Wang Z, Sun J, Xu G. Aberrant Functional Network Connectivity as a Biomarker of Generalized Anxiety Disorder. Front Hum Neurosci. 2017;11:626.29375339
145 Pantazatos SP, Talati A, Schneier FR, Hirsch J. Reduced anterior temporal and hippocampal functional connectivity during face processing discriminates individuals with social anxiety disorder from healthy controls and panic disorder, and increases following treatment. Neuropsychopharmacology. 2014;39(2):425–434.24084831
146 Frick A, Engman J, Alaie I, . Neuroimaging, genetic, clinical, and demographic predictors of treatment response in patients with social anxiety disorder. J Affect Disord. 2020;261:230–237.31655378
147 Whitfield-Gabrieli S, Ghosh SS, Nieto-Castanon A, . Brain connectomics predict response to treatment in social anxiety disorder. Mol Psychiatry. 2016;21(5):680–685.26260493
148 Price RB, Cummings L, Gilchrist D, . Towards personalized, brain-based behavioral intervention for transdiagnostic anxiety: Transient neural responses to negative images predict outcomes following a targeted computer-based intervention. J Consult Clin Psychol. 2018;86(12):1031–1045.30507228
149 Klumpp H, Roberts J, Kennedy AE, . Emotion regulation related neural predictors of cognitive behavioral therapy response in social anxiety disorder. Prog Neuropsychopharmacol Biol Psychiatry. 2017;75:106–112.28126372
150 Hahn T, Kircher T, Straube B, . Predicting treatment response to cognitive behavioral therapy in panic disorder with agoraphobia by integrating local neural information. JAMA Psychiatry. 2015;72(1):68–74.25409415
151 Hozer F, Houenou J. Can neuroimaging disentangle bipolar disorder? J Affect Disord. 2016;195:199–214.26896814
152 Khosla A, Khandnor P, Chand T. Automated diagnosis of depression from EEG signals using traditional and deep learning approaches: A comparative analysis. Biocybernetics and Biomedical Engineering. 2022;42(1):108–142.
153 Scheepens DS, van Waarde JA, Lok A, de Vries G, Denys D, van Wingen GA. The Link Between Structural and Functional Brain Abnormalities in Depression: A Systematic Review of Multimodal Neuroimaging Studies. Front Psychiatry. 2020;11:485.32581868
154 Sinha P, Joshi H, Ithal D. Resting State Functional Connectivity of Brain With Electroconvulsive Therapy in Depression: Meta-Analysis to Understand Its Mechanisms. Front Hum Neurosci. 2020;14:616054.33551779
155 Fullana MA, Abramovitch A, Via E, . Diagnostic biomarkers for obsessive-compulsive disorder: A reasonable quest or ignis fatuus? Neurosci Biobehav Rev. 2020;118:504–513.32866526
156 Esterman M, Stumps A, Jagger-Rickels A, . Evaluating the evidence for a neuroimaging subtype of posttraumatic stress disorder. Sci Transl Med. 2020;12(568).
157 Dalgleish T, Black M, Johnston D, Bevan A. Transdiagnostic approaches to mental health problems: Current status and future directions. J Consult Clin Psychol. 2020;88(3):179–195.32068421
158 Gillan CM, Seow TXF. Carving Out New Transdiagnostic Dimensions for Research in Mental Health. Biol Psychiatry Cogn Neurosci Neuroimaging. 2020;5(10):932–934.32532686
159 Yucel M, Oldenhof E, Ahmed SH, . A transdiagnostic dimensional approach towards a neuropsychological assessment for addiction: an international Delphi consensus study. Addiction. 2019;114(6):1095–1109.30133930
160 Kozlov M. Your brain expands and shrinks over time - these charts show how. Nature. 2022;604(7905):230–231.35388158
161 ABCD Research Consortium. Adolescent Brain Cognitive Development (ABCD) Study. https://abcdstudy.org/about/. Accessed September 13, 2022.
162 Biobank UK. https://www.ukbiobank.ac.uk/. Accessed September 13, 2022.
163 Achalia R, Sinha A, Jacob A, . A proof of concept machine learning analysis using multimodal neuroimaging and neurocognitive measures as predictive biomarker in bipolar disorder. Asian J Psychiatr. 2020;50:101984.32143176
164 Ambrosi E, Arciniegas DB, Madan A, . Insula and amygdala resting-state functional connectivity differentiate bipolar from unipolar depression. Acta Psychiatr Scand. 2017;136(1):129–139.28369737
165 Arns M, Cerquera A, Gutierrez RM, Hasselman F, Freund JA. Non-linear EEG analyses predict non-response to rTMS treatment in major depressive disorder. Clin Neurophysiol. 2014;125(7):1392–1399.24360132
166 Arns M, Drinkenburg WH, Fitzgerald PB, Kenemans JL. Neurophysiological predictors of non-response to rTMS in depression. Brain Stimul. 2012;5(4):569–576.22410477
167 Arribas JI, Calhoun VD, Adali T. Automatic Bayesian classification of healthy controls, bipolar disorder, and schizophrenia using intrinsic connectivity maps from FMRI data. IEEE Trans Biomed Eng. 2010;57(12):2850–2860.20876002
168 Bachmann M, Lass J, Hinrikus H. Single channel EEG analysis for detection of depression. Biomedical Signal Processing and Control. 2017;31:391–397.
169 Bailey NW, Hoy KE, Rogasch NC, . Responders to rTMS for depression show increased fronto-midline theta and theta connectivity compared to non-responders. Brain Stimul. 2018;11(1):190–203.29128490
170 Baranger D, Halchenko Y, Satz S, . Aberrant Levels of Cortical Myelin Distinguish Individuals With Unipolar Depression From Healthy Controls. Biological Psychiatry. 2021;89(9):S364.
171 Bares M, Novak T, Vlcek P, Hejzlar M, Brunovsky M. Early change of prefrontal theta cordance and occipital alpha asymmetry in the prediction of responses to antidepressants. Int J Psychophysiol. 2019;143:1–8.31195067
172 Bares M, Novak T, Brunovsky M, Kopecek M, Hoschl C. The Comparison of Effectiveness of Various Potential Predictors of Response to Treatment With SSRIs in Patients With Depressive Disorder. J Nerv Ment Dis. 2017;205(8):618–626.27660994
173 Bares M, Novak T, Kopecek M, Brunovsky M, Stopkova P, Hoschl C. The effectiveness of prefrontal theta cordance and early reduction of depressive symptoms in the prediction of antidepressant treatment outcome in patients with resistant depression: analysis of naturalistic data. Eur Arch Psychiatry Clin Neurosci. 2015;265(1):73–82.24848366
174 Bartlett EA, DeLorenzo C, Sharma P, . Pretreatment and early-treatment cortical thickness is associated with SSRI treatment response in major depressive disorder. Neuropsychopharmacology. 2018;43(11):2221–2230.29955151
175 Baskaran A, Farzan F, Milev R, . The comparative effectiveness of electroencephalographic indices in predicting response to escitalopram therapy in depression: A pilot study. J Affect Disord. 2018;227:542–549.29169123
176 Bi K, Chattun MR, Liu X, . Abnormal early dynamic individual patterns of functional networks in low gamma band for depression recognition. J Affect Disord. 2018;238:366–374.29908476
177 Brandt IM, Kohler-Forsberg K, Ganz M, . Reward processing in major depressive disorder and prediction of treatment response - Neuropharm study. Eur Neuropsychopharmacol. 2021;44:23–33.33455816
178 Burger C, Redlich R, Grotegerd D, . Differential Abnormal Pattern of Anterior Cingulate Gyrus Activation in Unipolar and Bipolar Depression: an fMRI and Pattern Classification Approach. Neuropsychopharmacology. 2017;42(7):1399–1408.28205606
179 Cash RFH, Cocchi L, Anderson R, . A multivariate neuroimaging biomarker of individual outcome to transcranial magnetic stimulation in depression. Hum Brain Mapp. 2019;40(16):4618–4629.31332903
180 Chen Q, Bi Y, Zhao X, . Regional amplitude abnormities in the major depressive disorder: A resting-state fMRI study and support vector machine analysis. J Affect Disord. 2022;308:1–9.35398104
181 Chen ST, Ku LC, Chen SJ, Shen TW. The Changes of qEEG Approximate Entropy during Test of Variables of Attention as a Predictor of Major Depressive Disorder. Brain Sci. 2020;10(11).
182 Chen VC, Wong FT, Tsai YH, . Convolutional Neural Network-Based Deep Learning Model for Predicting Differential Suicidality in Depressive Patients Using Brain Generalized q-Sampling Imaging. J Clin Psychiatry. 2021;82(2).
183 Cheng Y, Xu J, Arnone D, . Resting-state brain alteration after a single dose of SSRI administration predicts 8-week remission of patients with major depressive disorder. Psychol Med. 2017;47(3):438–450.27697079
184 Chin Fatt CR, Jha MK, Cooper CM, . Effect of Intrinsic Patterns of Functional Brain Connectivity in Moderating Antidepressant Treatment Response in Major Depression. Am J Psychiatry. 2020;177(2):143–154.31537090
185 Colle R, Chupin M, Cury C, . Depressed suicide attempters have smaller hippocampus than depressed patients without suicide attempts. J Psychiatr Res. 2015;61:13–18.25555305
186 Cook IA, Hunter AM, Caudill MM, Abrams MJ, Leuchter AF. Prospective testing of a neurophysiologic biomarker for treatment decisions in major depressive disorder: The PRISE-MD trial. J Psychiatr Res. 2020;124:159–165.32169689
187 Costafreda SG, Fu CH, Picchioni M, . Pattern of neural responses to verbal fluency shows diagnostic specificity for schizophrenia and bipolar disorder. BMC Psychiatry. 2011;11:18.21276242
188 Crane NA, Jenkins LM, Bhaumik R, . Multidimensional prediction of treatment response to antidepressants with cognitive control and functional MRI. Brain. 2017;140(2):472–486.28122876
189 Crowther A, Smoski MJ, Minkel J, . Resting-state connectivity predictors of response to psychotherapy in major depressive disorder. Neuropsychopharmacology. 2015;40(7):1659–1673.25578796
190 de la Salle S, Jaworska N, Blier P, Smith D, Knott V. Using prefrontal and midline right frontal EEG-derived theta cordance and depressive symptoms to predict the differential response or remission to antidepressant treatment in major depressive disorder. Psychiatry Res Neuroimaging. 2020;302:111109.32480044
191 Duan L, Duan H, Qiao Y, . Machine Learning Approaches for MDD Detection and Emotion Decoding Using EEG Signals. Front Hum Neurosci. 2020;14:284.33173472
192 Dunlop BW, Rajendra JK, Craighead WE, . Functional Connectivity of the Subcallosal Cingulate Cortex And Differential Outcomes to Treatment With Cognitive-Behavioral Therapy or Antidepressant Medication for Major Depressive Disorder. Am J Psychiatry. 2017;174(6):533–545.28335622
193 Ellard KK, Zimmerman JP, Kaur N, . Functional Connectivity Between Anterior Insula and Key Nodes of Frontoparietal Executive Control and Salience Networks Distinguish Bipolar Depression From Unipolar Depression and Healthy Control Subjects. Biol Psychiatry Cogn Neurosci Neuroimaging. 2018;3(5):473–484.29580768
194 Erguzel TT, Ozekes S, Gultekin S, Tarhan N, Hizli Sayar G, Bayram A. Neural Network Based Response Prediction of rTMS in Major Depressive Disorder Using QEEG Cordance. Psychiatry Investig. 2015;12(1):61–65.
195 Erguzel TT, Ozekes S, Gultekin S, Tarhan N. Ant Colony Optimization Based Feature Selection Method for QEEG Data Classification. Psychiatry Investig. 2014;11(3):243–250.
196 Fang P, Zeng LL, Shen H, . Increased cortical-limbic anatomical network connectivity in major depression revealed by diffusion tensor imaging. PLoS One. 2012;7(9):e45972.23049910
197 Farb NAS, Desormeau P, Anderson AK, Segal ZV. Static and treatment-responsive brain biomarkers of depression relapse vulnerability following prophylactic psychotherapy: Evidence from a randomized control trial. Neuroimage Clin. 2022;34:102969.35367955
198 Feder S, Sundermann B, Wersching H, . Sample heterogeneity in unipolar depression as assessed by functional connectivity analyses is dominated by general disease effects. J Affect Disord. 2017;222:79–87.28679115
199 Gao Y, Wang X, Xiong Z, . Abnormal Fractional Amplitude of Low-Frequency Fluctuation as a Potential Imaging Biomarker for First-Episode Major Depressive Disorder: A Resting-State fMRI Study and Support Vector Machine Analysis. Front Neurol. 2021;12:751400.34912284
200 Gao C, Xu Z, Tan T, . Combination of spontaneous regional brain activity and HTR1A/1B DNA methylation to predict early responses to antidepressant treatments in MDD. J Affect Disord. 2022;302:249–257.35092755
201 Gartner M, Ghisu ME, Scheidegger M, . Aberrant working memory processing in major depression: evidence from multivoxel pattern classification. Neuropsychopharmacology. 2018;43(9):1972–1979.29777198
202 Ge R, Downar J, Blumberger DM, Daskalakis ZJ, Vila-Rodriguez F. Functional connectivity of the anterior cingulate cortex predicts treatment outcome for rTMS in treatment-resistant depression at 3-month follow-up. Brain Stimul. 2020;13(1):206–214.31668646
203 Ge R, Downar J, Blumberger DM, Daskalakis ZJ, Lam RW, Vila-Rodriguez F. Structural network integrity of the central executive network is associated with the therapeutic effect of rTMS in treatment resistant depression. Prog Neuropsychopharmacol Biol Psychiatry. 2019;92:217–225.30685322
204 Godlewska BR, Browning M, Norbury R, Igoumenou A, Cowen PJ, Harmer CJ. Predicting Treatment Response in Depression: The Role of Anterior Cingulate Cortex. Int J Neuropsychopharmacol. 2018;21(11):988–996.30124867
205 Godlewska BR, Browning M, Norbury R, Cowen PJ, Harmer CJ. Early changes in emotional processing as a marker of clinical response to SSRI treatment in depression. Transl Psychiatry. 2016;6(11):e957.27874847
206 Goldstein-Piekarski AN, Staveland BR, Ball TM, Yesavage J, Korgaonkar MS, Williams LM. Intrinsic functional connectivity predicts remission on antidepressants: a randomized controlled trial to identify clinically applicable imaging biomarkers. Transl Psychiatry. 2018;8(1):57.29507282
207 Gong Q, Li L, Du M, . Quantitative prediction of individual psychopathology in trauma survivors using resting-state FMRI. Neuropsychopharmacology. 2014;39(3):681–687.24064470
208 Gong Q, Li L, Tognin S, . Using structural neuroanatomy to identify trauma survivors with and without post-traumatic stress disorder at the individual level. Psychol Med. 2014;44(1):195–203.23551879
209 Gong Q, Wu Q, Scarpazza C, . Prognostic prediction of therapeutic response in depression using high-field MR imaging. Neuroimage. 2011;55(4):1497–1503.21134472
210 Gosnell SN, Curtis KN, Velasquez K, . Habenular connectivity may predict treatment response in depressed psychiatric inpatients. J Affect Disord. 2019;242:211–219.30195174
211 Grieve SM, Korgaonkar MS, Gordon E, Williams LM, Rush AJ. Prediction of nonremission to antidepressant therapy using diffusion tensor imaging. J Clin Psychiatry. 2016;77(4):e436–443.27137427
212 Grotegerd D, Stuhrmann A, Kugel H, . Amygdala excitability to subliminally presented emotional faces distinguishes unipolar and bipolar depression: an fMRI and pattern classification study. Hum Brain Mapp. 2014;35(7):2995–3007.24038516
213 Guo M, Wang T, Zhang Z, . Diagnosis of major depressive disorder using whole-brain effective connectivity networks derived from resting-state functional MRI. J Neural Eng. 2020;17(5):056038.32987369
214 Guo W, Cui X, Liu F, . Decreased interhemispheric coordination in the posterior default-mode network and visual regions as trait alterations in first-episode, drug-naive major depressive disorder. Brain Imaging Behav. 2018;12(5):1251–1258.29143911
215 Guo H, Cao X, Liu Z, Li H, Chen J, Zhang K. Machine learning classifier using abnormal brain network topological metrics in major depressive disorder. Neuroreport. 2012;23(17):1006–1011.23044496
216 Guo WB, Liu F, Chen JD, . Abnormal neural activity of brain regions in treatment-resistant and treatment-sensitive major depressive disorder: a resting-state fMRI study. J Psychiatr Res. 2012;46(10):1366–1373.22835912
217 Hahn T, Marquand AF, Ehlis AC, . Integrating neurobiological markers of depression. Arch Gen Psychiatry. 2011;68(4):361–368.21135315
218 Hasanzadeh F, Mohebbi M, Rostami R. Graph theory analysis of directed functional brain networks in major depressive disorder based on EEG signal. J Neural Eng. 2020;17(2):026010.32053813
219 Hasanzadeh F, Mohebbi M, Rostami R. Prediction of rTMS treatment response in major depressive disorder using machine learning techniques and nonlinear features of EEG signal. J Affect Disord. 2019;256:132–142.31176185
220 Hellewell SC, Welton T, Maller JJ, . Profound and reproducible patterns of reduced regional gray matter characterize major depressive disorder. Transl Psychiatry. 2019;9(1):176.31341158
221 Hopman HJ, Chan SMS, Chu WCW, . Personalized prediction of transcranial magnetic stimulation clinical response in patients with treatment-refractory depression using neuroimaging biomarkers and machine learning. J Affect Disord. 2021;290:261–271.34010751
222 Hou Z, Kong Y, Yin Y, Zhang Y, Yuan Y. Identification of first-episode unmedicated major depressive disorder using pretreatment features of dominant coactivation patterns. Prog Neuropsychopharmacol Biol Psychiatry. 2021;104:110038.32682877
223 Hou Z, Kong Y, He X, Yin Y, Zhang Y, Yuan Y. Increased temporal variability of striatum region facilitating the early antidepressant response in patients with major depressive disorder. Prog Neuropsychopharmacol Biol Psychiatry. 2018;85:39–45.29608926
224 Hou Z, Gong L, Zhi M, . Distinctive pretreatment features of bilateral nucleus accumbens networks predict early response to antidepressants in major depressive disorder. Brain Imaging Behav. 2018;12(4):1042–1052.28971301
225 Hou Z, Song X, Jiang W, . Prognostic value of imbalanced interhemispheric functional coordination in early therapeutic efficacy in major depressive disorder. Psychiatry Res Neuroimaging. 2016;255:1–8.27497214
226 Hu X, Zhang L, Hu X, . Abnormal Hippocampal Subfields May Be Potential Predictors of Worse Early Response to Antidepressant Treatment in Drug-Naive Patients With Major Depressive Disorder. J Magn Reson Imaging. 2019;49(6):1760–1768.30295348
227 Ichikawa N, Lisi G, Yahata N, . Primary functional brain connections associated with melancholic major depressive disorder and modulation by antidepressants. Sci Rep. 2020;10(1):3542.32103088
228 Jaworska N, Blondeau C, Tessier P, . Examining relations between alpha power as well as anterior cingulate cortex-localized theta activity and response to single or dual antidepressant pharmacotherapies. J Psychopharmacol. 2014;28(6):587–595.24557661
229 Jaworska N, Blondeau C, Tessier P, . Response prediction to antidepressants using scalp and source-localized loudness dependence of auditory evoked potential (LDAEP) slopes. Prog Neuropsychopharmacol Biol Psychiatry. 2013;44:100–107.23360662
230 Jiang C, Li Y, Tang Y, Guan C. Enhancing EEG-Based Classification of Depression Patients Using Spatial Information. IEEE Trans Neural Syst Rehabil Eng. 2021;29:566–575.33587703
231 Jiang H, Dai Z, Lu Q, Yao Z. Magnetoencephalography resting-state spectral fingerprints distinguish bipolar depression and unipolar depression. Bipolar Disord. 2020;22(6):612–620.31729112
232 Jiang R, Abbott CC, Jiang T, . SMRI Biomarkers Predict Electroconvulsive Treatment Outcomes: Accuracy with Independent Data Sets. Neuropsychopharmacology. 2018;43(5):1078–1087.28758644
233 Kipli K, Kouzani AZ. Degree of contribution (DoC) feature selection algorithm for structural brain MRI volumetric features in depression detection. Int J Comput Assist Radiol Surg. 2015;10(7):1003–1016.25418867
234 Koller-Schlaud K, Strohle A, Barwolf E, Behr J, Rentzsch J. EEG Frontal Asymmetry and Theta Power in Unipolar and Bipolar Depression. J Affect Disord. 2020;276:501–510.32871681
235 Koo PC, Berger C, Kronenberg G, . Combined cognitive, psychomotor and electrophysiological biomarkers in major depressive disorder. Eur Arch Psychiatry Clin Neurosci. 2019;269(7):823–832.30392042
236 Korgaonkar MS, Rekshan W, Gordon E, . Magnetic Resonance Imaging Measures of Brain Structure to Predict Antidepressant Treatment Outcome in Major Depressive Disorder. EBioMedicine. 2015;2(1):37–45.26137532
237 Korgaonkar MS, Williams LM, Song YJ, Usherwood T, Grieve SM. Diffusion tensor imaging predictors of treatment outcomes in major depressive disorder. Br J Psychiatry. 2014;205(4):321–328.24970773
238 Kraus C, Klobl M, Tik M, . The pulvinar nucleus and antidepressant treatment: dynamic modeling of antidepressant response and remission with ultra-high field functional MRI. Mol Psychiatry. 2019;24(5):746–756.29422521
239 Leaver AM, Wade B, Vasavada M, . Fronto-Temporal Connectivity Predicts ECT Outcome in Major Depression. Front Psychiatry. 2018;9:92.29618992
240 Lee TW, Wu YT, Yu YW, Chen MC, Chen TJ. The implication of functional connectivity strength in predicting treatment response of major depressive disorder: a resting EEG study. Psychiatry Res. 2011;194(3):372–377.22041534
241 Li R, Yang J, Li L, . Integrating Multilevel Functional Characteristics Reveals Aberrant Neural Patterns during Audiovisual Emotional Processing in Depression. Cereb Cortex. 2021;32(1):1–14.34642754
242 Li CT, Cheng CM, Juan CH, . Task-Modulated Brain Activity Predicts Antidepressant Responses of Prefrontal Repetitive Transcranial Magnetic Stimulation: A Randomized Sham-Control Study. Chronic Stress (Thousand Oaks). 2021;5:24705470211006855.33889790
243 Li H, Song S, Wang D, . Individualized diagnosis of major depressive disorder via multivariate pattern analysis of thalamic sMRI features. BMC Psychiatry. 2021;21(1):415.34416848
244 Li J, Chen H, Fan F, . White-matter functional topology: a neuromarker for classification and prediction in unmedicated depression. Transl Psychiatry. 2020;10(1):365.33127899
245 Li H, Cui L, Cao L, . Identification of bipolar disorder using a combination of multimodality magnetic resonance imaging and machine learning techniques. BMC Psychiatry. 2020;20(1):488.33023515
246 Li CT, Cheng CM, Chen MH, . Antidepressant Efficacy of Prolonged Intermittent Theta Burst Stimulation Monotherapy for Recurrent Depression and Comparison of Methods for Coil Positioning: A Randomized, Double-Blind, Sham-Controlled Study. Biol Psychiatry. 2020;87(5):443–450.31563272
247 Li M, Das T, Deng W, . Clinical utility of a short resting-state MRI scan in differentiating bipolar from unipolar depression. Acta Psychiatr Scand. 2017;136(3):288–299.28504840
248 Li Y, Dai X, Wu H, Wang L. Establishment of Effective Biomarkers for Depression Diagnosis With Fusion of Multiple Resting-State Connectivity Measures. Front Neurosci. 2021;15:729958.34566570
249 Liao W, Li J, Duan X, Cui Q, Chen H, Chen H. Static and dynamic connectomics differentiate between depressed patients with and without suicidal ideation. Hum Brain Mapp. 2018;39(10):4105–4118.29962025
250 Liu W, Zhang C, Wang X, . Functional connectivity of major depression disorder using ongoing EEG during music perception. Clin Neurophysiol. 2020;131(10):2413–2422.32828045
251 Liu Y, Admon R, Mellem MS, . Machine Learning Identifies Large-Scale Reward-Related Activity Modulated by Dopaminergic Enhancement in Major Depression. Biol Psychiatry Cogn Neurosci Neuroimaging. 2020;5(2):163–172.31784354
252 Liu F, Xie B, Wang Y, . Characterization of post-traumatic stress disorder using resting-state fMRI with a multi-level parametric classification approach. Brain Topogr. 2015;28(2):221–237.25078561
253 Liu F, Guo W, Yu D, . Classification of different therapeutic responses of major depressive disorder with multivariate pattern analysis method based on structural MR scans. PLoS One. 2012;7(7):e40968.22815880
254 Lord A, Horn D, Breakspear M, Walter M. Changes in community structure of resting state functional connectivity in unipolar depression. PLoS One. 2012;7(8):e41282.22916105
255 Lu F, Cui Q, He Z, . Prefrontal-limbic-striatum dysconnectivity associated with negative emotional endophenotypes in bipolar disorder during depressive episodes. J Affect Disord. 2021;295:422–430.34507222
256 Lu Q, Jiang H, Luo G, Han Y, Yao Z. Multichannel matching pursuit of MEG signals for discriminative oscillation pattern detection in depression. Int J Psychophysiol. 2013;88(2):206–212.23623951
257 Manelis A, Iyengar S, Swartz HA, Phillips ML. Prefrontal cortical activation during working memory task anticipation contributes to discrimination between bipolar and unipolar depression. Neuropsychopharmacology. 2020;45(6):956–963.32069475
258 Matsuo K, Harada K, Fujita Y, . Distinctive Neuroanatomical Substrates for Depression in Bipolar Disorder versus Major Depressive Disorder. Cereb Cortex. 2019;29(1):202–214.29202177
259 Matsuoka K, Yasuno F, Kishimoto T, . Microstructural Differences in the Corpus Callosum in Patients With Bipolar Disorder and Major Depressive Disorder. J Clin Psychiatry. 2017;78(1):99–104.27574839
260 Meng Q, Zhang A, Cao X, . Brain Imaging Study on the Pathogenesis of Depression & Therapeutic Effect of Selective Serotonin Reuptake Inhibitors. Psychiatry Investig. 2020;17(7):688–694.
261 Meyer BM, Rabl U, Huemer J, . Prefrontal networks dynamically related to recovery from major depressive disorder: a longitudinal pharmacological fMRI study. Transl Psychiatry. 2019;9(1):64.30718459
262 Modinos G, Mechelli A, Pettersson-Yeo W, Allen P, McGuire P, Aleman A. Pattern classification of brain activation during emotional processing in subclinical depression: psychosis proneness as potential confounding factor. PeerJ. 2013;1:e42.23638379
263 Mohammadi M, Al-Azab F, Raahemi B, . Data mining EEG signals in depression for their diagnostic value. BMC Med Inform Decis Mak. 2015;15:108.26699540
264 Mourao-Miranda J, Almeida JR, Hassel S, . Pattern recognition analyses of brain activation elicited by happy and neutral faces in unipolar and bipolar depression. Bipolar Disord. 2012;14(4):451–460.22631624
265 Mulders PCR, Llera A, Beckmann CF, . Structural changes induced by electroconvulsive therapy are associated with clinical outcome. Brain Stimul. 2020;13(3):696–704.32289700
266 Mumtaz W, Qayyum A. A deep learning framework for automatic diagnosis of unipolar depression. Int J Med Inform. 2019;132:103983.31586827
267 Mumtaz W, Malik AS. A Comparative Study of Different EEG Reference Choices for Diagnosing Unipolar Depression. Brain Topogr. 2018;31(5):875–885.29860588
268 Mumtaz W, Ali SSA, Yasin MAM, Malik AS. A machine learning framework involving EEG-based functional connectivity to diagnose major depressive disorder (MDD). Med Biol Eng Comput. 2018;56(2):233–246.28702811
269 Mumtaz W, Xia L, Mohd Yasin MA, Azhar Ali SS, Malik AS. A wavelet-based technique to predict treatment outcome for Major Depressive Disorder. PLoS One. 2017;12(2):e0171409.28152063
270 Mumtaz W, Xia L, Ali SSA, Yasin MAM, Hussain M, Malik AS. Electroencephalogram (EEG)-based computer-aided technique to diagnose major depressive disorder (MDD). Biomedical Signal Processing and Control. 2017;31:108–115.
271 Nguyen KP, Fatt CC, Treacher A, Mellema C, Trivedi MH, Montillo A. Predicting Response to the Antidepressant Bupropion using Pretreatment fMRI. Predict Intell Med. 2019;11843:53–62.31709423
272 Nicholson AA, Densmore M, McKinnon MC, . Machine learning multivariate pattern analysis predicts classification of posttraumatic stress disorder and its dissociative subtype: a multimodal neuroimaging approach. Psychol Med. 2019;49(12):2049–2059.30306886
273 Nogovitsyn N, Muller M, Souza R, . Hippocampal tail volume as a predictive biomarker of antidepressant treatment outcomes in patients with major depressive disorder: a CAN-BIND report. Neuropsychopharmacology. 2020;45(2):283–291.31610545
274 Nord CL, Halahakoon DC, Limbachya T, . Neural predictors of treatment response to brain stimulation and psychological therapy in depression: a double-blind randomized controlled trial. Neuropsychopharmacology. 2019;44(9):1613–1622.31039579
275 Olbrich S, Sander C, Minkwitz J, . EEG vigilance regulation patterns and their discriminative power to separate patients with major depression from healthy controls. Neuropsychobiology. 2012;65(4):188–194.22538271
276 Oliveira-Maia AJ, Press D, Pascual-Leone A. Modulation of motor cortex excitability predicts antidepressant response to prefrontal cortex repetitive transcranial magnetic stimulation. Brain Stimul. 2017;10(4):787–794.28438543
277 Yang J, Palaniyappan L, Xi C, . Aberrant integrity of the cortico-limbic-striatal circuit in major depressive disorder with suicidal ideation. J Psychiatr Res. 2022;148:277–285.35180634
278 Pang Y, Zhang H, Cui Q, . Combined static and dynamic functional connectivity signatures differentiating bipolar depression from major depressive disorder. Aust N Z J Psychiatry. 2020;54(8):832–842.32456443
279 Qin K, Lei D, Pinaya WHL, . Using graph convolutional network to characterize individuals with major depressive disorder across multiple imaging sites. EBioMedicine. 2022;78:103977.35367775
280 Qin J, Shen H, Zeng LL, Jiang W, Liu L, Hu D. Predicting clinical responses in major depression using intrinsic functional connectivity. Neuroreport. 2015;26(12):675–680.26164454
281 Qin J, Wei M, Liu H, . Abnormal hubs of white matter networks in the frontal-parieto circuit contribute to depression discrimination via pattern classification. Magn Reson Imaging. 2014;32(10):1314–1320.25179136
282 Qiu L, Huang X, Zhang J, . Characterization of major depressive disorder using a multiparametric classification approach based on high resolution structural images. Journal of psychiatry & neuroscience : JPN. 2014;39(2):78–86.24083459
283 Rabinoff M, Kitchen CM, Cook IA, Leuchter AF. Evaluation of quantitative EEG by classification and regression trees to characterize responders to antidepressant and placebo treatment. Open Med Inform J. 2011;5:1–8.21603560
284 Redlich R, Almeida JJ, Grotegerd D, . Brain morphometric biomarkers distinguishing unipolar and bipolar depression. A voxel-based morphometry-pattern classification approach. JAMA Psychiatry. 2014;71(11):1222–1230.25188810
285 Rentzsch J, Adli M, Wiethoff K, Gomez-Carrillo de Castro A, Gallinat J. Pretreatment anterior cingulate activity predicts antidepressant treatment response in major depressive episodes. Eur Arch Psychiatry Clin Neurosci. 2014;264(3):213–223.23873091
286 Rive MM, Redlich R, Schmaal L, . Distinguishing medication-free subjects with unipolar disorder from subjects with bipolar disorder: state matters. Bipolar Disord. 2016;18(7):612–623.27870505
287 Rocha-Rego V, Jogia J, Marquand AF, Mourao-Miranda J, Simmons A, Frangou S. Examination of the predictive value of structural magnetic resonance scans in bipolar disorder: a pattern classification approach. Psychol Med. 2014;44(3):519–532.23734914
288 Rottstaedt F, Weidner K, Strauss T, . Size matters - The olfactory bulb as a marker for depression. J Affect Disord. 2018;229:193–198.29324366
289 Rubin-Falcone H, Zanderigo F, Thapa-Chhetry B, . Pattern recognition of magnetic resonance imaging-based gray matter volume measurements classifies bipolar disorder and major depressive disorder. J Affect Disord. 2018;227:498–505.29156364
290 Sacchet MD, Livermore EE, Iglesias JE, Glover GH, Gotlib IH. Subcortical volumes differentiate Major Depressive Disorder, Bipolar Disorder, and remitted Major Depressive Disorder. J Psychiatr Res. 2015;68:91–98.26228406
291 Sadat Shahabi M, Shalbaf A, Maghsoudi A. Prediction of drug response in major depressive disorder using ensemble of transfer learning with convolutional neural network based on EEG. Biocybernetics and Biomedical Engineering. 2021;41(3):946–959.
292 Sankar A, Zhang T, Gaonkar B, . Diagnostic potential of structural neuroimaging for depression from a multi-ethnic community sample. BJPsych Open. 2016;2(4):247–254.27703783
293 Schultz J, Becker B, Preckel K, . Improving therapy outcome prediction in major depression using multimodal functional neuroimaging: A pilot study. Personalized Medicine in Psychiatry. 2018;11–12:7–15.
294 Shalbaf R, Brenner C, Pang C, . Non-linear Entropy Analysis in EEG to Predict Treatment Response to Repetitive Transcranial Magnetic Stimulation in Depression. Front Pharmacol. 2018;9:1188.30425640
295 Shan X, Qiu Y, Pan P, . Disrupted Regional Homogeneity in Drug-Naive Patients With Bipolar Disorder. Front Psychiatry. 2020;11:825.32922322
296 Shan X, Cui X, Liu F, . Shared and distinct homotopic connectivity changes in melancholic and non-melancholic depression. J Affect Disord. 2021;287:268–275.33799047
297 Shao J, Dai Z, Zhu R, . Early identification of bipolar from unipolar depression before manic episode: Evidence from dynamic rfMRI. Bipolar Disord. 2019;21(8):774–784.31407477
298 Shi Y, Zhang L, He C, . Sleep disturbance-related neuroimaging features as potential biomarkers for the diagnosis of major depressive disorder: A multicenter study based on machine learning. J Affect Disord. 2021;295:148–155.34461370
299 Shimizu Y, Yoshimoto J, Toki S, . Toward Probabilistic Diagnosis and Understanding of Depression Based on Functional MRI Data Analysis with Logistic Group LASSO. PLoS One. 2015;10(5):e0123524.25932629
300 Siegle GJ, Thompson WK, Collier A, . Toward clinically useful neuroimaging in depression treatment: prognostic utility of subgenual cingulate activity for determining depression outcome in cognitive therapy across studies, scanners, and patient characteristics. Arch Gen Psychiatry. 2012;69(9):913–924.22945620
301 Squarcina L, Dagnew TM, Rivolta MW, Bellani M, Sassi R, Brambilla P. Automated cortical thickness and skewness feature selection in bipolar disorder using a semi-supervised learning method. J Affect Disord. 2019;256:416–423.31229930
302 Stange JP, Jenkins LM, Pocius S, . Using resting-state intrinsic network connectivity to identify suicide risk in mood disorders. Psychol Med. 2020;50(14):2324–2334.31597581
303 Stoyanov D, Kandilarova S, Paunova R, Barranco Garcia J, Latypova A, Kherif F. Cross-Validation of Functional MRI and Paranoid-Depressive Scale: Results From Multivariate Analysis. Front Psychiatry. 2019;10:869.31824359
304 Sun F, Liu Z, Yang J, Fan Z, Yang J. Differential Dynamical Pattern of Regional Homogeneity in Bipolar and Unipolar Depression: A Preliminary Resting-State fMRI Study. Front Psychiatry. 2021;12:764932.34966303
305 Sun K, Liu Z, Chen G, . A two-center radiomic analysis for differentiating major depressive disorder using multi-modality MRI data under different parcellation methods. J Affect Disord. 2022;300:1–9.34942222
306 Sun F, Liu Z, Fan Z, Zuo J, Xi C, Yang J. Dynamical regional activity in putamen distinguishes bipolar type I depression and unipolar depression. J Affect Disord. 2022;297:94–101.34678402
307 Sverdlov O, Curcic J, Hannesdottir K, . A Study of Novel Exploratory Tools, Digital Technologies, and Central Nervous System Biomarkers to Characterize Unipolar Depression. Front Psychiatry. 2021;12:640741.34025472
308 Tang Q, Cui Q, Chen Y, . Shared and distinct changes in local dynamic functional connectivity patterns in major depressive and bipolar depressive disorders. J Affect Disord. 2022;298(Pt A):43–50.34715198
309 Tenke CE, Kayser J, Manna CG, . Current source density measures of electroencephalographic alpha predict antidepressant treatment response. Biol Psychiatry. 2011;70(4):388–394.21507383
310 Uyulan C, de la Salle S, Erguzel TT, . Depression Diagnosis Modeling With Advanced Computational Methods: Frequency-Domain eMVAR and Deep Learning. Clin EEG Neurosci. 2022;53(1):24–36.34080925
311 van Waarde JA, Scholte HS, van Oudheusden LJ, Verwey B, Denys D, van Wingen GA. A functional MRI marker may predict the outcome of electroconvulsive therapy in severe and treatment-resistant depression. Mol Psychiatry. 2015;20(5):609–614.25092248
312 Voineskos D, Blumberger DM, Zomorrodi R, . Altered Transcranial Magnetic Stimulation-Electroencephalographic Markers of Inhibition and Excitation in the Dorsolateral Prefrontal Cortex in Major Depressive Disorder. Biol Psychiatry. 2019;85(6):477–486.30503506
313 Wade BSC, Sui J, Njau S, . Data-Driven Cluster Selection for Subcortical Shape and Cortical Thickness Predicts Recovery from Depressive Symptoms. Proc IEEE Int Symp Biomed Imaging. 2017;2017:502–506.30713592
314 Wade BSC, Sui J, Hellemann G, . Inter and intra-hemispheric structural imaging markers predict depression relapse after electroconvulsive therapy: a multisite study. Transl Psychiatry. 2017;7(12):1270.29217832
315 Wang Y, Gong N, Fu C. Major depression disorder diagnosis and analysis based on structural magnetic resonance imaging and deep learning. J Integr Neurosci. 2021;20(4):977–984.34997720
316 Wang Y, Sun K, Liu Z, . Classification of Unmedicated Bipolar Disorder Using Whole-Brain Functional Activity and Connectivity: A Radiomics Analysis. Cereb Cortex. 2020;30(3):1117–1128.31408101
317 Wang Y, Wang J, Jia Y, . Topologically convergent and divergent functional connectivity patterns in unmedicated unipolar depression and bipolar disorder. Transl Psychiatry. 2017;7(7):e1165.28675389
318 Wang X, Ren Y, Zhang W. Depression Disorder Classification of fMRI Data Using Sparse Low-Rank Functional Brain Network and Graph-Based Features. Comput Math Methods Med. 2017;2017:3609821.28487746
319 Wu Z, Wang C, Ma Z, . Abnormal functional connectivity of habenula in untreated patients with first-episode major depressive disorder. Psychiatry Res. 2020;285:112837.32044600
320 Wu P, Zhang A, Sun N, . Cortical Thickness Predicts Response Following 2 Weeks of SSRI Regimen in First-Episode, Drug-Naive Major Depressive Disorder: An MRI Study. Front Psychiatry. 2021;12:751756.35273524
321 Wu MJ, Mwangi B, Bauer IE, . Identification and individualized prediction of clinical phenotypes in bipolar disorders using neurocognitive data, neuroimaging scans and machine learning. Neuroimage. 2017;145(Pt B):254–264.26883067
322 Xi C, Liu Z, Zeng C, . The centrality of working memory networks in differentiating bipolar type I depression from unipolar depression: A task-fMRI study. Can J Psychiatry. 2022:7067437221078646.
323 Xiao H, Yuan M, Li H, . Functional connectivity of the hippocampus in predicting early antidepressant efficacy in patients with major depressive disorder. J Affect Disord. 2021;291:315–321.34077821
324 Xue L, Pei C, Wang X, . Predicting Neuroimaging Biomarkers for Antidepressant Selection in Early Treatment of Depression. J Magn Reson Imaging. 2021;54(2):551–559.33634921
325 Yan B, Xu X, Liu M, . Quantitative Identification of Major Depression Based on Resting-State Dynamic Functional Connectivity: A Machine Learning Approach. Front Neurosci. 2020;14:191.32292322
326 Yan DD, Zhao LL, Song XW, Zang XH, Yang LC. Automated detection of clinical depression based on convolution neural network model. Biomed Tech (Berl). 2022;67(2):131–142.35142145
327 Yan M, Cui X, Liu F, . Abnormal Default-Mode Network Homogeneity in Melancholic and Nonmelancholic Major Depressive Disorder at Rest. Neural Plast. 2021;2021:6653309.33995525
328 Yan M, He Y, Cui X, . Disrupted Regional Homogeneity in Melancholic and Non-melancholic Major Depressive Disorder at Rest. Front Psychiatry. 2021;12:618805.33679477
329 Yang J, Zhang M, Ahn H, . Development and evaluation of a multimodal marker of major depressive disorder. Hum Brain Mapp. 2018;39(11):4420–4439.30113112
330 Yang J, Yin Y, Zhang Z, . Predictive brain networks for major depression in a semi-multimodal fusion hierarchical feature reduction framework. Neurosci Lett. 2018;665:163–169.29217258
331 Yang J, Pu W, Ouyang X, . Abnormal Connectivity Within Anterior Cortical Midline Structures in Bipolar Disorder: Evidence From Integrated MRI and Functional MRI. Front Psychiatry. 2019;10:788.31736805
332 Yang H, Li L, Peng H, . Alterations in regional homogeneity of resting-state brain activity in patients with major depressive disorder screening positive on the 32-item hypomania checklist (HCL-32). J Affect Disord. 2016;203:69–76.27280965
333 Yoshida K, Shimizu Y, Yoshimoto J, . Prediction of clinical depression scores and detection of changes in whole-brain using resting-state functional MRI data with partial least squares regression. PLoS One. 2017;12(7):e0179638.28700672
334 Yu H, Li F, Wu T, . Functional brain abnormalities in major depressive disorder using the Hilbert-Huang transform. Brain Imaging Behav. 2018;12(6):1556–1568.29427063
335 Zeng LL, Shen H, Liu L, . Identifying major depression using whole-brain functional connectivity: a multivariate pattern analysis. Brain. 2012;135(Pt 5):1498–1507.22418737
336 Zhang A, Wang X, Li J, . Resting-State fMRI in Predicting Response to Treatment With SSRIs in First-Episode, Drug-Naive Patients With Major Depressive Disorder. Front Neurosci. 2022;16:831278.35250466
337 Zhang B, Liu S, Liu X, . Discriminating subclinical depression from major depression using multi-scale brain functional features: A radiomics analysis. J Affect Disord. 2022;297:542–552.34744016
338 Zhang Q, Wu Q, Zhu H, . Multimodal MRI-Based Classification of Trauma Survivors with and without Post-Traumatic Stress Disorder. Front Neurosci. 2016;10:292.27445664
339 Zhao J, Huang J, Zhi D, . Functional network connectivity (FNC)-based generative adversarial network (GAN) and its applications in classification of mental disorders. J Neurosci Methods. 2020;341:108756.32380227
340 Zhao L, Wang Y, Jia Y, . Microstructural Abnormalities of Basal Ganglia and Thalamus in Bipolar and Unipolar Disorders: A Diffusion Kurtosis and Perfusion Imaging Study. Psychiatry Investig. 2017;14(4):471–482.
341 Zhdanov A, Atluri S, Wong W, . Use of Machine Learning for Predicting Escitalopram Treatment Outcome From Electroencephalography Recordings in Adult Patients With Depression. JAMA Netw Open. 2020;3(1):e1918377.31899530
342 Zheng Y, Chen X, Li D, . Treatment-naive first episode depression classification based on high-order brain functional network. J Affect Disord. 2019;256:33–41.31158714
343 Zhong X, Shi H, Ming Q, . Whole-brain resting-state functional connectivity identified major depressive disorder: A multivariate pattern analysis in two independent samples. J Affect Disord. 2017;218:346–352.28499208
344 Zhu Z, Lei D, Qin K, . Combining Deep Learning and Graph-Theoretic Brain Features to Detect Posttraumatic Stress Disorder at the Individual Level. Diagnostics (Basel). 2021;11(8).
345 Zhu X, Yuan F, Zhou G, . Cross-network interaction for diagnosis of major depressive disorder based on resting state functional connectivity. Brain Imaging Behav. 2021;15(3):1279–1289.32734435
346 Zhu H, Yuan M, Qiu C, . Multivariate classification of earthquake survivors with post-traumatic stress disorder based on large-scale brain networks. Acta Psychiatr Scand. 2020;141(3):285–298.31997301
347 Zhu J, Cai H, Yuan Y, . Variance of the global signal as a pretreatment predictor of antidepressant treatment response in drug-naive major depressive disorder. Brain Imaging Behav. 2018;12(6):1768–1774.29473140
348 Zhu Y, Qi S, Zhang B, . Connectome-Based Biomarkers Predict Subclinical Depression and Identify Abnormal Brain Connections With the Lateral Habenula and Thalamus. Front Psychiatry. 2019;10:371.31244688
349 Bruun CF, Arnbjerg CJ, Kessing LV. Electroencephalographic Parameters Differentiating Melancholic Depression, Non-melancholic Depression, and Healthy Controls. A Systematic Review. Front Psychiatry. 2021;12:648713.34489747
350 Cohen SE, Zantvoord JB, Wezenberg BN, Bockting CLH, van Wingen GA. Magnetic resonance imaging for individual prediction of treatment response in major depressive disorder: a systematic review and meta-analysis. Transl Psychiatry. 2021;11(1):168.33723229
351 De Crescenzo F, Ciliberto M, Menghini D, Treglia G, Ebmeier KP, Janiri L. Is (18)F-FDG-PET suitable to predict clinical response to the treatment of geriatric depression? A systematic review of PET studies. Aging Ment Health. 2017;21(9):889–894.27792402
352 Dichter GS, Gibbs D, Smoski MJ. A systematic review of relations between resting-state functional-MRI and treatment response in major depressive disorder. J Affect Disord. 2015;172:8–17.25451389
353 Enneking V, Leehr EJ, Dannlowski U, Redlich R. Brain structural effects of treatments for depression and biomarkers of response: a systematic review of neuroimaging studies. Psychol Med. 2020;50(2):187–209.31858931
354 Fu CH, Steiner H, Costafreda SG. Predictive neural biomarkers of clinical response in depression: a meta-analysis of functional and structural neuroimaging studies of pharmacological and psychological therapies. Neurobiol Dis. 2013;52:75–83.22659303
355 Gillett G, Tomlinson A, Efthimiou O, Cipriani A. Predicting treatment effects in unipolar depression: A meta-review. Pharmacol Ther. 2020;212:107557.32437828
356 Levy A, Taib S, Arbus C, . Neuroimaging Biomarkers at Baseline Predict Electroconvulsive Therapy Overall Clinical Response in Depression: A Systematic Review. J ECT. 2019;35(2):77–83.30628993
357 Long Z, Du L, Zhao J, Wu S, Zheng Q, Lei X. Prediction on treatment improvement in depression with resting state connectivity: A coordinate-based meta-analysis. J Affect Disord. 2020;276:62–68.32697717
358 Masse-Sibille C, Djamila B, Julie G, Emmanuel H, Pierre V, Gilles C. Predictors of Response and Remission to Antidepressants in Geriatric Depression: A Systematic Review. J Geriatr Psychiatry Neurol. 2018;31(6):283–302.30477416
359 Siegel-Ramsay JE, Bertocci MA, Wu B, Phillips ML, Strakowski SM, Almeida JRC. Distinguishing between depression in bipolar disorder and unipolar depression using magnetic resonance imaging: a systematic review. Bipolar Disord. 2022.
360 Simon L, Blay M, Galvao F, Brunelin J. Using EEG to Predict Clinical Response to Electroconvulsive Therapy in Patients With Major Depression: A Comprehensive Review. Front Psychiatry. 2021;12:643710.34248695
361 van der Vinne N, Vollebregt MA, van Putten M, Arns M. Frontal alpha asymmetry as a diagnostic marker in depression: Fact or fiction? A meta-analysis. Neuroimage Clin. 2017;16:79–87.28761811
362 Widge AS, Bilge MT, Montana R, . Electroencephalographic Biomarkers for Treatment Response Prediction in Major Depressive Illness: A Meta-Analysis. Am J Psychiatry. 2019;176(1):44–56.30278789
363 Librenza-Garcia D, Kotzian BJ, Yang J, . The impact of machine learning techniques in the study of bipolar disorder: A systematic review. Neurosci Biobehav Rev. 2017;80:538–554.28728937
364 Seeberg I, Kjaerstad HL, Miskowiak KW. Neural and Behavioral Predictors of Treatment Efficacy on Mood Symptoms and Cognition in Mood Disorders: A Systematic Review. Front Psychiatry. 2018;9(JUL):337.30093870
365 Whalley HC, Papmeyer M, Sprooten E, Lawrie SM, Sussmann JE, McIntosh AM. Review of functional magnetic resonance imaging studies comparing bipolar disorder and schizophrenia. Bipolar Disord. 2012;14(4):411–431.22631622
366 Colvonen PJ, Glassman LH, Crocker LD, . Pretreatment biomarkers predicting PTSD psychotherapy outcomes: A systematic review. Neurosci Biobehav Rev. 2017;75:140–156.28143760
367 Nelson MD, Tumpap AM. Posttraumatic stress disorder symptom severity is associated with left hippocampal volume reduction: a meta-analytic study. CNS Spectr. 2017;22(4):363–372.27989265
368 Haghbayan H, Boutin A, Laflamme M, . The Prognostic Value of MRI in Moderate and Severe Traumatic Brain Injury: A Systematic Review and Meta-Analysis. Crit Care Med. 2017;45(12):e1280–e1288.29028764
369 Hulkower MB, Poliak DB, Rosenbaum SB, Zimmerman ME, Lipton ML. A decade of DTI in traumatic brain injury: 10 years and 100 articles later. AJNR Am J Neuroradiol. 2013;34(11):2064–2074.23306011
370 Raji CA, Tarzwell R, Pavel D, . Clinical utility of SPECT neuroimaging in the diagnosis and treatment of traumatic brain injury: a systematic review. PLoS One. 2014;9(3):e91088.24646878
371 Qing X, Gu L, Li D. Abnormalities of Localized Connectivity in Obsessive-Compulsive Disorder: A Voxel-Wise Meta-Analysis. Front Hum Neurosci. 2021;15:739175.34602998
372 Santos VA, Carvalho DD, Van Ameringen M, Nardi AE, Freire RC. Neuroimaging findings as predictors of treatment outcome of psychotherapy in anxiety disorders. Prog Neuropsychopharmacol Biol Psychiatry. 2019;91:60–71.29627509
373 Xu J, Van Dam NT, Feng C, . Anxious brain networks: A coordinate-based activation likelihood estimation meta-analysis of resting-state functional connectivity studies in anxiety. Neurosci Biobehav Rev. 2019;96:21–30.30452934