# ABBREVIATIONS TABLE

Abbreviation: Definition
AHRQ EPC: Agency for Healthcare Research and Quality Evidence-based Practice Center
ASL: Arterial spin labeling
BDI: Beck Depression Inventory
CAPS: Clinician Administered PTSD Scale
DAISY: DistillerSR’s Artificial Intelligence System
DTI: Diffusion tensor imaging
ECT: Electroconvulsive therapy
EEG: Evoked potentials and electroencephalogram
ESP: Evidence Synthesis Program
fMRI: Functional magnetic resonance imaging
GOSE: Glasgow Outcome Scale-Extended
HAM-A: Hamilton Anxiety Rating Scale
HAM-D: Hamilton Depression Rating Scale
KQ: Key Question
MADRS: Montgomery-Asberg Depression Rating Scale
MEG: Magnetoencephalography
MeSH: Medical Subject Headings
MINI: Mini-International Neuropsychiatric Interview
MRI: Magnetic resonance imaging
OCD: Obsessive compulsive disorder
PCL: PTSD Checklist
PET: Positron emission tomography
PHQ: Patient Health Questionnaire
PTSD: Posttraumatic stress disorder
RCT: Randomized controlled trial
rTMS: Repetitive transcranial magnetic stimulation
SCID: Structured Clinical Interview for DSM
SHA305: Commander John Scott Hannon Veterans Mental Health Care Improvement Act, Public Law 116-171, section 305
SPECT: Single photon emission computed tomography
SUD: Substance use disorder
TBI: Traumatic brain injury
TBS: Theta burst stimulation
tDCS: Transcranial direct current stimulation
US: United States
VA: Department of Veterans Affairs
Y-BOCS: Yale Brown Obsessive Compulsive Scale
YMRS: Young Mania Rating Scale