# DISCUSSION

## SUMMARY OF KEY FINDINGS

To assist the VA with determining next steps in the application of precision medicine to Veterans’ healthcare and research, we conducted an evidence map of neuroimaging and neurophysiologic biomarkers in mental health and TBI. We identified 313 eligible primary studies and 30 eligible systematic reviews. The majority of primary studies (70%) and reviews (57%) addressed depression, while fewer studies and reviews examined other conditions of interest. Most primary studies used MRI-based neuroimaging techniques (75%) and a fifth employed EEG (22%). Two-thirds of primary studies (64%) focused on diagnosis for conditions of interest, and nearly all of these (91%) were cross-sectional. Half of primary studies (52%) employed machine learning to analyze neuroimaging or neurophysiologic data and develop diagnostic or prognostic models. Primary studies generally included young and middle-aged adults, with only 5 studies having participants with mean ages of 65 or older. Studies were conducted in diverse locations around the world, with the most common being China (35%) and the US or Canada (30%); very few studies (5%) were conducted in more than 1 country. Overall, most of the evidence came from very small studies. For example, among 98 studies using structural and/or functional MRI to address diagnosis for depression, 51% had less than 100 participants, while only 5% had 500 or more participants. Only 14 primary studies included US Veterans or active military service members; 12 addressed PTSD and/or TBI, and 2 evaluated SUD.

Key findings for primary studies include:

- Many studies evaluated the use of structural or functional MRI in diagnosis and prognosis of depression, but there were important methodological concerns:
  ○ Nearly all diagnostic studies were cross-sectional, small in size, and included participants with variable past histories of symptoms and treatments.
  ○ Prognostic studies mostly focused on response to antidepressants, and were also generally small.
- A substantial number of studies used EEG for diagnosis and prognosis of depression, but these had similar methodological issues as noted above.
- Most studies on bipolar disorder were small and cross-sectional, included participants with depression, and focused on diagnosis.
- Studies evaluating PTSD were small and cross-sectional, and mainly used structural or functional MRI to address diagnosis.
- Studies examining TBI were small and cross-sectional, often included participants with co-occurring PTSD, and mainly used structural or functional MRI to address diagnosis.
- Studies on SUD used structural or functional MRI and EEG, most addressed alcohol use disorder, and half evaluated prediction of relapse or response to treatment.
- Studies on OCD and anxiety disorders were small and cross-sectional, mainly used structural or functional MRI, and focused on diagnosis.
- Fourteen studies included US Veterans, addressing PTSD and/or TBI, or SUD:
  ○ All 11 diagnostic studies were cross-sectional, 2 prognostic studies were cohorts, and 1 was an RCT.
- None evaluated prediction of adverse or side effects from treatments.

## IMPLICATIONS FOR VA POLICY

We found a large number of studies mainly using MRI-based techniques to evaluate diagnosis and prognosis for depression, but there were substantial methodological limitations for the majority of this evidence. Additionally, none of the depression studies were conducted with US Veterans or military service members. Given that neuroimaging tests are costly and time-consuming to conduct (and analyze), it is not clear that using such tests adds value in the clinical setting or that they could replace current standards for diagnosis of depression, which involve structured interviews and clinician assessments. Regarding prognosis, neuroimaging techniques may potentially aid in predicting early response and/or selection of appropriate therapies, but most studies included participants with variable histories of symptoms and past treatments. Only 2 studies focused on participants with their first episode of depression. Furthermore, no study evaluated prediction of adverse or side effects of treatments, whereas this is often an important factor in patient and clinician decisions to stop or switch antidepressants. There were fewer studies using EEG to examine depression, and this evidence base has similar limitations as that evaluating MRI-based techniques. Thus, it is unclear how these data could be incorporated into current clinical practice to improve diagnosis or treatment selection and/or monitoring for depression. Future systematic reviews focused on these techniques for diagnosis and/or prognosis in depression may also be needed to better characterize their potential utility for clinical care.

We found considerably less evidence addressing other mental health conditions and TBI, and fewer studies using other neuroimaging and neurophysiologic techniques. Although there were some studies on PTSD, TBI, and SUD that included US Veterans or military service members; overall, these shared the same methodological limitations as noted above. Therefore, it also appears premature to implement MRI (and other neuroimaging and neurophysiologic techniques) in the clinical diagnosis and treatment of these other conditions.

## GAPS IN EVIDENCE AND FUTURE RESEARCH

As noted above, there are important methodological concerns regarding the evidence on neuroimaging and neurophysiological techniques for evaluating diagnosis and prognosis of mental health conditions and TBI. While there are a large number of studies examining depression (using MRI or EEG), these are largely small in sample size and the majority used cross-sectional data to evaluate diagnosis. Additionally, participants often had variable trajectories of symptoms and treatments preceding data collection. These study design issues have been previously noted as contributing to problems with replicability and validity of neuroimaging and neurophysiologic studies in mental health.^15,18,156^ Whereas most of the identified primary studies had less than 100 participants, current estimates are that thousands of individuals are needed to provide stable and valid results regarding important associations between neuroimaging findings and clinical phenotypes.^15^ Furthermore, to account for changes in brain structure and functioning over time, current recommendations are to use comparisons with age-standardized findings (developed from large populations),^18^ instead of using data from small samples of age-matched controls. To better understand clinical phenotypes, it is also important to have longitudinal data on symptoms and exposures, in addition to considering transdiagnostic dimensional approaches.^157–159^ Having data before certain exposures may be particularly important for studies evaluating PTSD and TBI.

The acquisition and analysis of (longitudinal) data from a large number of individuals will likely require large ongoing investments in this research, as well as fundamental changes in research organization and incentives that currently promote competition and inhibit data sharing.^16,17,160^ Current projects that exemplify the level of resources, organization, and cooperation needed for such efforts include the Adolescent Brain Cognitive Development (ABCD) study in the US^161^ and the UK Biobank.^162^

Therefore, we recommend the following for future research:

- Consider investment in larger studies (thousands of participants) to identify reproducible and precise associations between neuroimaging and neurophysiologic findings and mental health phenotypes.
- Conduct longitudinal studies with data on exposures, symptoms, and neuroimaging and neurophysiologic data over the life course.
- Consider transdiagnostic approaches for describing mental health phenotypes.
- Particularly for addressing Veterans’ health and outcomes, develop longitudinal studies with initial data that precede combat and other service-related exposures.

## LIMITATIONS

We sought to identify and describe the evidence for a broad range of neuroimaging and neurophysiologic tests used to evaluate the diagnosis and prognosis of a large number of mental health conditions and TBI. Therefore, we conducted an evidence map that provides descriptive information about research studies examining these questions and highlights gaps in the existing evidence. Thus, we did not abstract detailed results on the factors included, nor performance metrics of, diagnostic or prognostic models using neuroimaging and/or neurophysiologic data. We also did not formally evaluate the quality of included primary studies or systematic reviews. Additionally, we employed machine learning techniques to assist with the selection of relevant studies and reviews; it is possible that we may have missed some eligible studies. We also limited our search of the evidence to English language studies and reviews.

## CONCLUSIONS

Most existing evidence on neuroimaging and neurophysiologic data for mental health conditions evaluated use of MRI for diagnosis and prognosis in depression. In addition to the lack of evidence on other conditions or using other types of neuroimaging and neurophysiologic data, existing studies were limited by small sample sizes and cross-sectional designs. These methodological concerns need to be addressed by future research using larger samples with longitudinal data. Existing evidence gaps and limitations indicate that it may be premature to apply neuroimaging and neurophysiologic tests to evaluate and treat mental health conditions and TBI in clinical settings.