# RESULTS

## OVERVIEW

From 50,989 unique search results, we identified 343 eligible articles (Figure 1), consisting of 313 primary studies (Appendix D) and 30 systematic reviews (Appendix E). At abstract screening, 47,586 results were excluded, with 54% of these based on low scores from a machine-learning algorithm (see Methods and Figure 1). A list of references excluded during full-text review (k = 3,060) and reasons for exclusion is available upon request.

Figure 1 Identification and Selection of Eligible Studies

Notes. * Machine-learning algorithm DAISY on the DistillerSR platform (Evidence Partners).

Most of the eligible primary studies and systematic reviews addressed depression (k = 236, 69%), while fewer studies and reviews evaluated other conditions. Only 2 primary studies evaluated genetic data in addition to neuroimaging or neurophysiologic data. Figure 2 summarizes the distribution of primary studies using various neuroimaging or neurophysiologic data for evaluation of diagnosis or prognosis of each condition of interest. Three-quarters of primary studies used MRI-based imaging techniques (k = 236, 75%), while a fifth used EEG data (k = 68, 22%). For multiple conditions, there were none or few studies (k ≤ 5) examining either diagnosis or prognosis.

Figure 2 Number of Primary Studies Using Neuroimaging or Neurophysiologic Data to Evaluate Diagnosis (A) or Prognosis (B) for Various Mental Health Conditions

Notes. Others category includes positron emission tomography (PET), single-photon emission computerized tomography (SPECT), and magnetoencephalography (MEG).

Abbreviations. ASL=arterial spin labeling; DTI=diffusion tensor imaging; EEG=electroencephalogram; MRI=magnetic resonance imaging (structural or functional); OCD=obsessive compulsive disorder; PTSD=posttraumatic stress disorder; SUD=substance use disorder; TBI=traumatic brain injury.

Table 1 provides more information about study populations and methods for primary studies across the different conditions. Most primary studies had small sample sizes, with only 9 having more than 500 participants (range 555–4541). Two-thirds of primary studies examined diagnosis (k = 200), 110 evaluated prognosis, and 3 addressed both diagnosis and prognosis. Most primary studies included young and middle-aged participants; only 5 studies had participants with mean ages of 65 or older, and all of these addressed depression (with 1 also including participants with bipolar disorder).^23–27^ Following Table 1, we present results for primary studies by condition of interest and then describe results for eligible systematic reviews.

Table 1 Summary of Characteristics of Included Primary Studies

| Depression (k = 218) | Bipolar Disorders (k = 47) | PTSD (k = 30) | TBI (k = 12) | SUD (k = 20) | OCD (k = 19) | Anxiety Disorders^a^ (k = 10)
Neuroimaging/Neurophysiologic technique
MRI-based techniques:
Structural MRI (sMRI) | 73 | 24 | 8 | 5 | 5 | 5 | 3
Functional MRI (fMRI) | 80 | 19 | 13 | 2 | 8 | 12 | 7
DTI or ASL | 12 | 5 | 1 | 2 | 2 | 1 | ―
EEG | 54 | 1 | 5 | 2 | 8 | 1 | ―
Others^b^ | 15 | 3 | 5 | 1 | ― | ― | ―
Outcomes
Diagnosis | 130 | 41 | 24 | 10 | 9 | 17 | 4
Prognosis:
Treatment response^c^ | 89 | 6 | 6 | | 11 | 2 | 6
Change in symptoms or functioning | 2 | ― | ― | 2 | ― | ― | ―
Study design & methods
Cross-sectional | 117 | 38 | 22 | 10 | 9 | 15 | 3
Cohort/longitudinal observational | 88 | 9 | 6 | 2 | 10 | 4 | 7
Randomized controlled trial | 13 | ― | 2 | ― | 1 | ― | ―
Used machine learning | 123 | 28 | 10 | 1 | 11 | 9 | 4
Models validated | 145 | 30 | 12 | 3 | 8 | 7 | 4
Country
US/Canada | 55 | 12 | 18 | 10 | 10 | 1 | 6
China | 84 | 9 | 7 | ― | 3 | 14 | 2
UK/Europe | 33 | 8 | 2 | ― | 2 | 1 | 1
Others^d^ | 44 | 17 | 3 | 2 | 5 | 3 | 1
NR | 2 | 1 | ― | ― | ― | ― | ―
Sample sizes (total N) ^e^
30–99 | 130 | 23 | 17 | 7 | 13 | 9 | 9
100–200 | 63 | 19 | 8 | 2 | 6 | 9 | 1
201–500 | 18 | 5 | 4 | 1 | ― | 1 | ―
501–1000 | 2 | ― | ― | ― | ― | ― | ―
>1,000 | 5 | ― | 1 | ― | 1 | ― | ―
Age (mean or median, years)
18–25 | 9 | 7 | 2 | ― | ― | 4 | 4
26–44 | 160 | 34 | 22 | 10 | 13 | 14 | 5
45–64 | 31 | 4 | 3 | 1 | 5 | ― | ―
>65 | 5 | 1 | ― | ― | ― | ― | ―
NR | 13 | 1 | 3 | 1 | 2 | 1 | 1
Type of Veterans included
US Veterans or active military | ― | ― | 10 | 7 | 3 | ― | ―
Non-US Veterans or active military | ― | ― | 3 | ― | ― | ― | ―

Notes.

a Includes general anxiety disorder, panic disorder, and social anxiety disorder.

b Includes positron emission tomography (PET), single-photon emission computerized tomography (SPECT), and magnetoencephalography (MEG).

c For SUD, this was abstinence vs relapse after or during treatment.

d Includes other countries not included in categories above, as well as studies done in multiple countries.

e Also includes healthy controls if among participants.

Abbreviations. ASL=arterial spin labeling; DTI=diffusion tensor imaging; EEG=electroencephalogram; MRI=magnetic resonance imaging; NR=not reported; OCD=obsessive compulsive disorder; PTSD=posttraumatic stress disorder; SUD=substance use disorder; TBI=traumatic brain injury; UK=United Kingdom; US=United States.

## DEPRESSION

### Overview

The majority of eligible primary studies evaluated depression (k = 218, 70%), and the vast majority of these used structural and/or functional MRI (k = 153) (Table 1). Fewer studies employed other MRI-based techniques like DTI (k = 10) and arterial spin labeling (ASL, k = 2). A quarter of studies addressing depression used EEG or evoked potentials (k = 54); others used magnetoencephalography (MEG, k = 8), PET (k = 4), or SPECT (k = 3). Most studies focused on whether neuroimaging tests contributed to diagnosis (k = 127). Less than half (k = 88) evaluated prognosis, and very few (k = 3) addressed both diagnosis and prognosis. About half of studies (k = 123) used machine learning methods to develop diagnostic or predictive models, including the selection of imaging features and patterns. Two-thirds of studies undertook model validation (k = 144). Most studies were very small with total sample sizes less than 100 (k = 130); only 2 studies had 500–1000 participants, and 5 studies had 1000 or more participants. Median sample size for studies using various neuroimaging or neurophysiologic data is shown in Figure 3. Studies were conducted in different regions of the world, with most common locations being the US or Canada (k = 55) and China (k = 84).

Figure 3 Median Sample Size of Included Studies Evaluating Diagnosis (A) or Prognosis (B) for Depression

Notes. Others category includes positron emission tomography (PET), single-photon emission computerized tomography (SPECT), and magnetoencephalography (MEG). Number of included studies is indicated for each type of imaging or neurophysiologic data.

Abbreviations. ASL=arterial spin labeling; DTI=diffusion tensor imaging; EEG=electroencephalogram; MRI=magnetic resonance imaging (structural or functional).

### MRI-based Imaging Techniques (Structural and Functional MRI, DTI, and ASL)

#### Diagnosis

Of 104 studies using MRI-based techniques to address diagnosis of depression, the largest proportion used structural MRI (k = 49), fMRI (k = 48; 39 using resting fMRI and 10 task-specific), or both (k = 1) (Table 2). A few used other MRI-based techniques like DTI (k = 6)^28–32^ and ASL (k = 2).^33,34^ Most were cross-sectional (k = 91), while those remaining were cohort/longitudinal (k = 13). Three-quarters used machine learning methods to develop models (k = 75). Nearly all studies assessed diagnostic model accuracy (k = 100) and sensitivity/specificity (k = 93). Three-quarters of the studies also undertook model validation (k = 77).

Total sample sizes ranged 30–4541; half of the studies had N < 100 (k = 57) and only 4 had N > 1000. Most included healthy controls (k = 99), while a quarter had participants with bipolar disorder (k = 26). A third focused particularly on participants not on medications (k = 34), with this including those who had not been on any medications and others who were not on medications at the time of the study. A fifth of studies included participants with their first episode of depression (k = 19). Nearly every study had substantial proportions of women (k = 92 with women >40%). Most participants were young and middle-aged; only 5 studies reported race. The most common locations were China (k = 57) and the US (k = 17).

The most frequently used standard for determining diagnostic accuracy was standardized clinician assessments (eg, k = 89 studies used Hamilton Depression Rating Scale [HAM-D]). Clinician interviews were also commonly used, including the Structured Clinical Interview for DSM (SCID; k = 74) and Mini-International Neuropsychiatric Interview (MINI; k = 18). Fewer studies used patient-reported measures such as the Beck Depression Inventory (BDI; k = 21).

Table 2 Summary of Characteristics of Included Studies Evaluating MRI-based Imaging Techniques for Diagnosis of Depression

| sMRI (k = 50) | fMRI (k = 49) | Other Techniques^a^ (k = 8)
Depression subgroups
Medication free | 14 | 19 | 2
First episode | 7 | 12 | ―
Treatment resistant | 1 | 2 | ―
Other groups included
Healthy controls | 46 | 47 | 6
Bipolar disorder patients | 12 | 12 | 3
Country
US | 13 | 6 | 4
China | 26 | 32 | 4
UK/Europe | 9 | 8 | ―
Other^b^ | 5 | 3 | ―
NR | 1 | ― | ―
Sample sizes (total N)
30–99 | 23 | 27 | 7
100–249 | 21 | 16 | 1
250–499 | 4 | 3 | ―
500–999 | ― | 1 | ―
>1,000 | 2 | 2 | ―
Age (mean or median, years)
18–25 | ― | 7 | 1
26–44 | 45 | 38 | 4
45–64 | 2 | 3 | ―
≥65 | 2 | 1 | 1
NR | 1 | ― | 2
% Women
0–15 | 1 | ― | ―
16–40 | 3 | 2 | ―
41–70 | 40 | 41 | 7
>70 | 5 | 6 | 1
NR | 1 | ― | ―
Race reported? | 4 | ― | 1
Diagnostic accuracy standard
Clinician interviews | 37 | 34 | 5
Clinician assessments | 40 | 35 | 5
Patient-reported outcomes | 8 | 9 | 1
Study design
Cross-sectional | 43 | 43 | 7
Cohort/longitudinal | 6 | 6 | 1
Analytic methods
Sensitivity/specificity | 44 | 45 | 7
Machine learning | 32 | 40 | 5
Models validated | 47 | 48 | 7

Notes.

a Includes arterial spin labeling (ASL) and diffusion tensor imaging (DTI).

b Includes other countries not included in categories above, as well as studies done in multiple countries.

Abbreviations. MRI=magnetic resonance imaging (structural or functional); NR=not reported.

#### Prognosis & Treatment Response

Among 59 studies evaluating prognosis, most also used structural MRI (k = 22), fMRI (k = 31; 15 resting fMRI, 14 task-specific, and 2 both resting and task), or both (k = 2); 5 studies used DTI. Nearly all studies examined treatment response (k = 55), most commonly to antidepressant therapy (k = 36). Fewer evaluated response to psychotherapy (k = 6), electroconvulsive therapy (ECT, k = 9), repetitive transcranial magnetic stimulation (rTMS, k = 5), transcranial direct current stimulation (tDCS, k = 1), theta burst stimulation (TBS, k = 1), or inpatient multi-modal treatment (k = 1) (Table 3). Additionally, 2 studies evaluated general trajectories over 2 years for middle-aged^35^ and older adults^26^ with depression. Twenty-two studies applied machine learning approaches and 34 validated predictive models.

Most studies were cohorts/longitudinal observational (k = 49), and 10 were reports of RCTs. Four of these articles^36–39^ used data from a single RCT, the international Study to Predict Optimized Treatment in Depression (iSPOT-D).^40^ A single study included N > 1000,^41^ while half had N < 100 participants (k = 31). Some studies on treatment response only included medication-free participants, indicating those who had not received treatment for the current depressive episode or had undergone a washout period (k = 24). Others focused on treatment-resistant depression (k = 11). Only 2 studies distinguished participants in their first episode of depression.^42,43^ Additionally, a third included healthy controls (k = 21), while a few had participants with bipolar disorder (k = 4). Studies had relatively young participants, and women were well represented. Demographic information relating to race/ethnicity was reported in 9 studies. The most common locations were the US or Canada (k = 21) and China (k = 12).

Table 3 Summary of Characteristics of Included Studies Evaluating MRI-based Techniques for Treatment Response in Depression

| Response to Treatments
| Antidepressants (k = 36) | Psychotherapies (k = 6) | ECT (k = 9) | rTMS (k = 6) | Other^a^ (k = 3)
Imaging technique
sMRI | 13 | ― | 7 | 2 | 1
fMRI | 20 | 6 | 3 | 5 | 1
DTI | 4 | ― | ― | ― | 1
Depression subgroups
Medication free | 20 | 3 | ― | ― | 2
Treatment resistant | 1 | ― | 6 | 4 | ―
Other groups included
Healthy controls | 16 | 3 | 1 | 3 | ―
Bipolar disorder | ― | ― | 4 | ― | ―
Country
US/Canada | 9 | 5 | 5 | 2 | 1
China | 11 | ― | ― | 1 | ―
UK/Europe | 5 | ― | ― | ― | 1
Other^b^ | 11 | 1 | 1 | 2 | 1
Sample sizes (total N)
30–99 | 18 | 3 | 7 | 4 | 1
100–249 | 15 | 3 | 2 | 1 | 2
250–499 | 3 | ― | ― | ― | ―
500–999 | ― | ― | ― | ― | ―
>1,000 | ― | ― | ― | 1 | ―
Age (mean or median, years)
26–44 | 27 | 5 | 4 | 5 | 2
45–64 | 5 | ― | 5 | 1 | 1
≥65 | 2 | ― | ― | ― | ―
NR | 2 | 1 | ― | ― | ―
% Women
0–15 | ― | 0 | ― | ― | ―
16–40 | 3 | 1 | ― | 1 | ―
41–70 | 27 | 2 | 6 | 5 | 3
>70 | 4 | 0 | ― | ― | ―
NR | 2 | 3 | 3 | 1 | ―
Race reported? | 4 | 2 | 2 | ― | ―
Study design
Cohort/longitudinal | 29 | 5 | 9 | 6 | 2
RCT | 7 | 1 | ― | ― | ―
Analytic methods
ROC (or sensitivity/specificity) | 17 | 3 | 2 | 4 | 1
Machine learning | 12 | 1 | 7 | 3 | ―
Models validated | 22 | 1 | 8 | 4 | 1

Notes.

a Includes 1 study on transcranial direct current stimulation (tDCS), 1 study on theta burst stimulation (TBS) vs rTMS, and 1 using multi-modal inpatient treatment.

b Includes other countries not included in categories above, as well as studies done in multiple countries.

Abbreviations. DTI=diffusion tensor imaging; ECT=electroconvulsive therapy; MRI=magnetic resonance imaging (structural or functional); NR=not reported; ROC=receiver operating curve; rTMS=repetitive transcranial magnetic stimulation.

### EEG and Evoked Potentials

#### Diagnosis

Of 54 studies evaluating EEG or evoked potentials for depression, 24 examined diagnosis (k = 24) (Table 4). Most studies addressing diagnosis included healthy controls (k = 23), and most were very small with total sample sizes less than 100 (k = 21). Only 2 studies focused on participants in their first episode of depression,^44,45^ and only 3 studies had more than 100 participants (range 157–400).^46–48^ Study participants were young and middle-aged adults (mean age range 20–55), and more than half of studies had more than 40% women (k = 17). Studies were conducted in different regions of the world, with the most common location being China (k = 7); 1 study was multi-site, occurring in Japan, the US, and Taiwan.^46^

All diagnostic studies were cross-sectional in design and most used machine learning methods (k = 17). Standardized clinician assessments (HAM-D and Montgomery-Asberg Depression Rating Scale [MADRS]) were the most frequently used diagnostic standard (k = 14). Most studies undertook model validation (k = 20).

#### Prognosis & Treatment Response

Thirty studies examined EEG or evoked potentials for prognosis in depression. These all examined response to specific treatments; most addressed outcomes after antidepressant therapy (k = 19), while fewer evaluated rTMS (k = 9) and 1 study each examined acupuncture^49^ or ketamine.^50^ A third of prognostic studies included participants who were not on medications (k = 11), and 8 focused on treatment-resistant participants (variably defined as not responding to sufficient course of antidepressants). No study included only participants with their first episode of depression. Six studies included participants who were healthy controls. The majority of studies were small with less than 100 participants (k = 22), while 8 studies included somewhat more participants (range 103–220). Studies most commonly were conducted in the US or Canada (k = 13).

Prognostic studies were most often longitudinal observational (k = 25) but a few used data from RCTs (k = 4).^51–54^ A third of prognostic studies used machine learning (k = 9). Studies most commonly used standardized clinician assessments (HAM-D and MADRS) to define treatment response (k = 25). Just under half of studies undertook model validation (k = 12).

Table 4 Characteristics of Included Studies Evaluating Electroencephalogram and Evoked Potentials for Depression

| Diagnosis (Total = 24) | Response to Treatments
| Diagnosis (Total = 24) | Antidepressants (Total = 19) | rTMS (Total = 9) | Other^a^ (Total = 2)
Depression subgroups
Medication free | 3 | 8 | ― | ―
Treatment resistant | ― | 3 | 1 | 1
Other groups included
Healthy controls | 23 | 3 | 2 | 1
Bipolar disorder | 2 | ― | ― | ―
Country
US/Canada | 3 | 10 | 3 | ―
China | 7 | 4 | ― | 1
UK/Europe | 5 | 4 | 1 | ―
Other^b^ | 9 | 5 | 3 | 1
NR | ― | ― | 1 | ―
Sample sizes (total N)
30–99 | 21 | 13 | 7 | 2
100–249 | 1 | 6 | 2 | ―
250–500 | 2 | ― | ― | ―
Age (mean or median, years)
18–35 | 5 | 3 | ― | ―
36–50 | 16 | 14 | 6 | 2
51–64 | 1 | ― | ― | ―
NR | 2 | 2 | 3 | ―
% Women
16–40 | 1 | 1 | ― | ―
41–70 | 14 | 15 | 6 | 1
>70 | 3 | 2 | ― | 1
NR | 6 | 1 | 3 | ―
Race reported? | ― | 2 | ― | ―
Diagnosis/prognosis standards
Clinician interviews | 9 | ― | ― | ―
Clinician assessments | 14 | 17 | 7 | 2
Patient-reported outcomes | 7 | 2 | 3 | ―
Study design
Cross-sectional | 24 | ― | ― | ―
Cohort/longitudinal observational | ― | 16 | 8 | 2
Randomized controlled trial | ― | 3 | 1 | ―
Analytic methods
Sensitivity/specificity | 23 | ― | 2 | ―
Machine learning | 17 | 5 | 3 | 2
Models validated | 20 | 6 | 4 | 2

Notes.

a Includes 1 study on outcomes after acupuncture and 1 on ketamine.

b Includes other countries not included in categories above, as well as studies done in multiple countries. Abbreviations. NR=not reported; rTMS=repetitive transcranial magnetic stimulation.

### Other Neuroimaging Techniques (MEG, PET, and SPECT)

Eight eligible studies evaluated MEG for depression; 7 of these examined diagnosis and 1 addressed treatment response to antidepressants.^55^ Five of these studies also used MRI-based imaging techniques. All diagnostic studies had healthy controls as comparators, and 1 also included individuals with bipolar disorder.^56^ All studies were conducted in China or Taiwan and were very small (total N = 41–108). Participants were young (mean age range 30–37) and women were well represented (37–61% across studies). Six diagnostic studies were cross-sectional, and 1 was a longitudinal cohort.^57^ All used structured interviews as the gold standard, and 6 also used HAM-D as the standardized clinician assessment. The prognostic study on outcomes with antidepressants also used HAM-D to define response.^55^ Three studies used machine learning methods, and 6 validated models.

We also identified 4 studies that evaluated PET for diagnosis (k = 2) or prognosis (k = 2) in depression. Three of these also used structural MRI to improve localization of PET data.^53,58,59^ Both diagnostic studies were cross-sectional and were conducted in the US.^58,59^ Both prognostic studies evaluated response to antidepressants and occurred in Taiwan; 1 was an RCT^53^ and the other an observational cohort.^60^ All studies were similarly very small (total N = 36–107) and included mostly young adults (mean age range 32–43). None of the studies used machine learning methods and none conducted model validation.

Lastly, 3 eligible studies used SPECT for diagnosis (k = 1) or prognosis (k = 2). The diagnostic study was very large (N = 4,541), conducted in the US, used a structured clinical interview (MINI) as the gold standard, and undertook model validation.^61^ Both prognostic studies were conducted by one research group in France, evaluated response to rTMS, and also included participants with bipolar disorder.^62,63^ They had small samples (total N = 33–58), and used patient-reported outcome (BDI) to determine response. None of the SPECT studies used a machine learning approach.

## BIPOLAR DISORDERS

Forty-seven eligible studies evaluated diagnosis (k = 41) or prognosis (k = 6) for bipolar disorders. More than half of studies also included participants with depression (k = 27 for diagnostic studies, and all prognostic studies). Nearly all diagnostic studies used MRI-based techniques (k = 24 for structural MRI, k = 19 fMRI [13 resting and 6 task-specific], k = 3 DTI, and k = 2 ASL), with 1 of these also using MEG.^56^ One study examined EEG for diagnosis.^64^ Half included healthy controls (k = 23), and half were very small with total N < 100 (k = 23). Only 3 studies had N > 250 (range 251–441).^65–67^ Most participants were young adults, with only 2 studies having mean ages of 45 or older.^27,62,68^ Most studies had at least 40% women (k = 44). The most common locations were China (k = 15) and the US (k = 12).

Most diagnostic studies were cross-sectional (k = 31), while 3 were longitudinal (to confirm symptoms and diagnosis over 1–2 years).^69–71^ About half of diagnostic studies used machine learning methods (k = 25), and undertook model validation (k = 24). Less than half used both structured clinical interviews (MINI and/or SCID) and standardized clinician assessments (Young Mania Rating Scale [YMRS]) as the diagnostic standard for bipolar disorder (k = 16). Another 18 studies used only structured interviews, and 3 used only YMRS. One study did not specifically identify structured interviews or a standardized assessment, indicating only that diagnosis was completed by a psychiatrist.^27^

All prognostic studies were included above in results for depression. Briefly, 4 used MRI-based techniques to evaluate outcomes after ECT^72–75^ and 2 used SPECT to examine response to rTMS.^62,63^ These were all small studies (total N = 33–122) of middle-aged adults (mean age range 39–56). Three studies used machine learning and validated models.^73–75^

## POSTTRAUMATIC STRESS DISORDER

### Overview

Thirty eligible articles evaluated PTSD, with most focusing on diagnosis (k = 24) (Table 5). The majority used MRI-based techniques, including fMRI (k = 11), structural MRI (k = 7), both structural MRI and fMRI (k = 1), or fMRI and DTI (k = 1). Remaining studies used PET (k = 1), SPECT (k = 2), MEG (k = 1), or EEG (k = 5). The majority were cross-sectional (k = 22), with fewer being longitudinal cohorts (k = 6) or RCT (k = 2). Most were small, with the majority having N < 100 (k = 17). The remaining sample sizes were 116–432 (k = 12) and 2,137 for 1 large database study.^76^ Studies were conducted mostly in the US or Canada (k = 18) and China (k = 7); a few were conducted in the Netherlands (k = 2), South Korea (k = 2), and Iran (k = 1). One third of the studies included US Veterans or active military (k = 10), with half of these including combat-exposed Veterans or active military (k = 5).

Table 5 Summary of Characteristics of Included Studies Addressing Diagnosis of Posttraumatic Stress Disorder

| sMRI (k = 6) | fMRI^a^ (k = 9) | DTI (k = 1) | EEG (Total=5) | Others^b^ (Total=6)
Population characteristics
Veteran or active military | 2 | 3 | 1 | 2 | 4
Combat exposed | 2 | 2 | 1 | 2 | 2
Included TBI | 1 | 2 | 1 | 1 | 2
Trauma-exposed controls | 5 | 1 | ― | ― | 2
Country
US/Canada | 2 | 4 | 1 | 3 | 6
China | 3 | 5 | ― | ― | ―
Other^c^ | 1 | ― | ― | 2 | ―
Sample sizes (total N)
30–99 | 4 | 4 | 1 | 4 | 2
100–249 | 2 | 4 | ― | 1 | 3
250–499 | ― | ― | ― | ― | 3
500–999 | ― | ― | ― | ― | ―
>1,000 | ― | 1 | ― | ― | ―
Age (mean or median, years)
26–44 | 4 | 7 | ― | 4 | 5
45–64 | 2 | ― | ― | 1 | ―
NR | ― | 1 | 1 | ― | ―
% Women
0–15 | 2 | 2 | ― | 3 | ―
16–40 | 1 | 1 | ― | ― | 3
41–70 | 3 | 3 | ― | 1 | 2
>70 | ― | 2 | ― | 1 | ―
NR | ― | 1 | 1 | ― | ―
Race reported? | 1 | 1 | ― | ― | 3
Diagnostic accuracy standard
Clinician interviews | 4 | 3 | ― | 3 | 4
Clinician assessments | 5 | 7 | 1 | 2 | 3
Patient-reported outcomes | 2 | 4 | 1 | 4 | ―
Study design
Cross-sectional | 5 | 8 | 1 | 5 | 6
Cohort/longitudinal | 1 | 1 | ― | ― | ―
Analytic methods
Sensitivity/specificity | 3 | 5 | ― | 5 | 3
Machine learning | 3 | 4 | ― | 2 | 2
Models validated | 2 | 4 | ― | 1 | 2

Notes.

a All resting fMRI studies.

b Includes positron emission tomography (PET), single-photon emission computerized tomography (SPECT), and magnetoencephalography (MEG).

c Includes other countries not included in categories above.

Abbreviations. DTI=diffusion tensor imaging; EEG=electroencephalogram; MRI=magnetic resonance imaging (structural or functional); NR=not reported; TBI=traumatic brain injury; US=United States.

### MRI-based Techniques (Structural and Functional MRI, and DTI)

#### Diagnosis

The majority of studies evaluating diagnosis for PTSD used MRI-based techniques (k = 14, Table 5). One of these used both MRI and MEG.^77^ Most of these were cross-sectional (k = 12), with only 2 being cohort studies.^78,79^ The majority of these studies were small in size, with half having N < 100 (k = 7), half with N = 116-217 (k = 6), and 1 large database study with N = 2,137 (this also included multiple mental health disorders).^76^ Participants were mostly young adults (mean age range 32–45), and women were variably represented (eg, 6 studies with no women). Half were conducted in China (k = 7), with the remaining from the US or Canada (k = 6) and South Korea (k = 1). The most commonly used diagnostic standards included structured interviews (SCID, k = 6) and clinician assessments (Clinician Administered PTSD Scale [CAPS], k = 8). Some also used patient-reported outcome measures such as the PTSD Checklist (PCL, k = 6). Six studies used machine learning to develop their models. All 14 studies addressed the accuracy of their predictive models, and 6 undertook model validation (Table 5). Five studies included US Veterans or active military populations, with 3 of these including combat-exposed persons; more information about these studies is provided in the section below.

#### Prognosis and Treatment Response

Six studies evaluated predictive models using structural MRI (k = 2)^80,81^ or fMRI (k = 4; 2 resting fMRI and 2 task-specific).^82–85^ All studies reported on predictive models for response to psychotherapy as treatment for PTSD, using CAPS to assess PTSD severity (Table 6). One study included both psychotherapy and TMS.^85^ Two studies were RCTs^82,85^ and the remaining were cohorts. Sample sizes ranged from 53–135, with most having N < 100 (k = 5). All studies included relatively young adults, with mean ages below 40 years of age. One study used machine learning methods,^84^ and 3 assessed model accuracy and validation.^80,84,85^ Two studies included combat-exposed Veterans, both conducted in the Netherlands.^80,81^

Table 6 Summary of Characteristics of Studies Evaluating MRI to Predict Response to Psychotherapy for Posttraumatic Stress Disorder

| Response to Psychotherapy (k = 6)
Population characteristics%
Veteran or active military | 3^a^
Combat exposed | 2^a^
TBI | ―
Comorbid alcohol use disorder | 1
Country
US | 4
Netherlands | 2
Sample sizes (total N)
30–99 | 5
100–140 | 1
Age (mean or median, years)
18–25 | 1
26–44 | 4
45–64 | ―
>65 | ―
NR | 1
% Women
0–15 | 3
16-–60 | ―
61–70 | 2
NR | 1
Race reported? | 1
Study design
Cohort/longitudinal | 4
RCT | 2
Measures of response or change
Clinician assessments | 6
Patient-reported outcomes | 1
Analytic methods
Machine learning | 1
Model accuracy assessed | 3
Models validated | 2

Notes.

a Includes 1 non-US Veteran study.

Abbreviations. MRI=magnetic resonance imaging; NR=not reported; RCT=randomized controlled trial; TBI=traumatic brain injury.

### EEG and Evoked Potentials

Five studies evaluated EEG for PTSD and all focused on diagnosis (Table 5).^47,86–89^ All were cross-sectional and only 1 had N > 100 (N = 157).^47^ Most were conducted in the US (k = 3), 1 in South Korea, and 1 in Iran. Most used clinical interviews (SCID [k = 3] and/or CAPS [k = 2]) as the diagnostic standard (k = 4),^47,86,87,89^ and 1 used only patient-reported measures.^88^ All assessed sensitivity and specificity, but only 1 undertook model validation.^86^

### Other Neuroimaging Techniques (MEG, SPECT, PET)

Six studies evaluated other imaging techniques, including MEG (k = 3),^77,90,91^ SPECT (k = 2),^92,93^ and PET (k = 1)^94^; all of these focused on diagnosis of PTSD and were cross-sectional (Table 5). Most were conducted in the US (k = 5), with N = 44–397. Three included US Veterans,^90,91,93^ and 2 also had participants with TBI.^92,93^ All used the SCID and/or CAPS as the diagnostic standard and assessed the accuracy of their models; 2 undertook model validation.^90,91^

### Studies in Veteran Populations

Thirteen studies were conducted in Veteran populations, most with US Veterans (k = 10)^76,82,86,89–91,93,95–97^, 2 with combat-exposed Veterans from the Netherlands,^80,81^ and 1 included combat-exposed members of the Canadian Armed Forces.^77^ We focus here on the 10 studies of US Veterans.

#### Diagnosis

Of the 10 studies in US Veteran populations, most evaluated diagnosis (k = 9)^76,86,89–91,93,95–97^. About half used MRI-based techniques (structural MRI k = 1, fMRI k = 4, DTI k = 1), while fewer used other methods (SPECT k = 1, MEG k = 2, EEG k = 2). Half of studies were conducted in populations who were also diagnosed with TBI (k = 5), all of which also included combat-exposed persons.^76,86,89–91,93,95–97^ These were relatively small studies with N = 32–196 and 4 studies with N < 100. The diagnostic standards included the SCID, CAPS, and patient-reported measures such as BDI, PCL, or PHQ. About half undertook model validation (k = 6).

#### Prognosis and Treatment Response

One small RCT (N = 53), conducted in a comorbid population with PTSD and alcohol use disorder, used fMRI data to predict response to an integrated psychotherapy for both conditions.^82^

## TRAUMATIC BRAIN INJURY

### Overview

Of 12 articles that addressed TBI, most evaluated diagnosis (k = 10) and the remaining 2 reported on prognosis of disability (Table 7). The majority used MRI-based techniques (k = 8) and fewer used EEG (k = 2), SPECT (k = 2), and MEG (k = 1). Most were cross-sectional (k = 10), small in size (eg, 9 studies with N < 100), and included younger populations (mean age <45). Half of the studies included PTSD populations; all of these focused on diagnosis and were cross-sectional, and 5 evaluated combat-exposed US Veterans.

Table 7 Summary of Characteristics of Included Studies Addressing Traumatic Brain Injury

| Diagnosis (k = 10) | Prediction of Disability (k = 2)
Neuroimaging/neurophysiologic technique
Structural MRI | 3 | 2
Functional MRI | 2 | ―
DTI | 2 | ―
SPECT | 2 | ―
MEG | 1 | ―
EEG | 2 | ―
Population characteristics
Veterans and/or active military | 7 | ―
Combat exposed | 7 | ―
PTSD | 6 | ―
Country
US | 10 | ―
Other^a^ | ― | 2
Sample sizes (total N)
30–99 | 5 | 2
100–199 | 2 | ―
>200 | 1 | ―
Age (mean or median, years)
18–25 | ― | ―
26–44 | 8 | 2
45–64 | 1 | ―
>65 | ― | ―
NR | 1 | ―
% Women
0–15 | 6 | ―
16–40 | 3 | 1
NR | 1 | 1
Race reported? | 6 | ―
Diagnosis/prognosis standard
Clinician interviews | 4 | ―
Clinician assessments | 6 | 2
Patient-reported outcomes | 5 | ―
Hospital records | 1 | ―
Study design
Cross-sectional | 10 | ―
Cohort/longitudinal | ― | 2
Analytic methods
Sensitivity/specificity (or PPV/NPV) | 7 | ―
Machine learning | ― | 1
Models validated | 3 | ―

Notes.

a Includes Taiwan and Norway.

Abbreviations. DTI=diffusor tensor imaging; EEG=electroencephalogram; fMRI=functional magnetic resonance imaging; MEG=magnetoencephalography; MRI=magnetic resonance imaging; NPV=negative predictive value; PPV=positive predictive value; PTSD=posttraumatic stress disorder; RCT=randomized controlled trial; SPECT=single-photon emission computerized tomography.

### MRI-based Techniques (Structural and Functional MRI, DTI, and ASL)

#### Diagnosis

The majority of identified studies evaluating diagnosis for TBI used MRI-based techniques (k = 6), including structural MRI (k = 3),^95,98,99^ fMRI (k = 2, both resting fMRI),^96,97^ and DTI (k = 2).^96,100^ One study also included MEG.^99^ All were cross-sectional studies conducted in the US. Diagnostic standards included patient-reported measures (k = 5), clinician assessments (k = 5), and structured clinical interviews (k = 1). Half assessed sensitivity and specificity (k = 3), and 2 undertook model validation. Most were small, with N < 100 (k = 5). Most included populations of US combat-exposed Veterans (k = 5).

#### Prognosis and Treatment Response

Both studies evaluating prognosis for TBI used MRI-based techniques. One was conducted in Taiwan^101^ and the other in Norway.^102^ Both were small cohort studies (N = 47–70) and investigated predictive models for global disability at least 1 year after injury, measured using the Glasgow Outcome Scale-Extended (GOSE). None included Veteran or active military populations.

### EEG and Other Neuroimaging Techniques

Two cross-sectional US-based studies evaluated EEG and both focused on diagnosis of TBI.^89,103^ One used hospital records as the indicator for TBI,^103^ and the other used the SCID.^89^ Both assessed sensitivity and specificity, but only 1 undertook model validation. Both were very small (N = 30–32). Two studies used SPECT to address diagnosis for TBI.^92,93^ Both included participants with PTSD, and are described in the PTSD section above.

### Studies in Veteran Populations

Seven studies included combat-exposed US Veteran populations.^89,93,95–97,99,100^ All focused on diagnosis and were cross-sectional, with most using MRI-based techniques (k = 5). One each used EEG, SPECT, or MEG (this study also used MRI).Most of these included participants with co-occurring PTSD and are described above (k = 5).^89,93,95–97^ The other 2 studies also had small samples (N = 84–109) of young and middle-aged adults (mean age 28–48).^99,100^

## SUBSTANCE USE DISORDERS

### Overview

Twenty studies addressed SUD, with the majority evaluating alcohol use disorder (k = 12) (Table 8).^82,104–114^ Remaining studies focused on cocaine use disorder (k = 3),^115–117^ opioid use disorder (k = 2),^118,119^ and methamphetamine use disorder (k = 3).^120–122^ More than half used structural and/or functional MRI (k = 12) or other MRI-based techniques (ASL, k = 2).^117,121^ Eight evaluated EEG or evoked potentials^98–100,102,104,105,110,111^; none used any other imaging techniques. About half focused on diagnosis (k = 9),^105,106,108,110,112,114,118,119,121^ while the rest evaluated prediction of relapse (k = 6) or treatment response (k = 5).^82,104,107,109,111,113,115–117,120,122^ Most evaluated the accuracy of their diagnostic or prognostic models (k = 16), and nearly half undertook model validation (k = 8). Most studies were very small with N < 100 (k = 14); 1 study had a total sample greater than 1000 (N = 1,376).^107^ About half used machine learning methods to develop models (k = 11). Studies were most commonly conducted in the US (k = 10) and China (k = 3).

Table 8 Summary of Characteristics of Included Studies Addressing Substance Use Disorder

| Diagnosis (k = 9) | Prognosis
| Diagnosis (k = 9) | Prediction of Relapse (k = 6) | Response to Treatment (k = 5)
Neuroimaging/Neurophysiologic technique
Structural MRI | 2 | 1 | 2
Functional MRI | 1 | 3 | 4
ASL | 1 | ― | 1
EEG | 6 | 2 | ―
Substance
Alcohol | 6 | 4 | 2
Opioid | 2 | ― | ―
Methamphetamine | 1 | 1 | 1
Cocaine | ― | 1 | 2
Population characteristics
Veterans and/or active military | ― | 1 | 2
Inpatient or residential treatment | 4 | 2 | 3
Country
US | 2 | 4 | 4
China | 2 | ― | 1
Europe | ― | 2 | ―
Other^a^ | 5 | ― | ―
Sample sizes (total N)
30–99 | 6 | 4 | 4
100–200 | 3 | 1 | 1
>1,000 | ― | 1 | ―
Age (mean or median, years)
18–25 | ― | ― | ―
26–44 | 5 | 5 | 4
45–64 | 3 | ― | 1
NR | 1 | 1 | ―
% Women
0–15 | 4 | 1 | 2
16–40 | 1 | 5 | 3
41–70 | 2 | ― | ―
NR | 2 | ― | ―
Race reported? | 1 | ― | 1
Included information on genetics? | ― | 1 | ―
Study design
Cohort/longitudinal | ― | 2 | 1
Cross-sectional | 9 | ― | ―
RCT | ― | ― | 1
Analytic methods
Machine learning | 6 | 4 | 1
Model accuracy assessed | 9 | 4 | 3
Models validated | 5 | 2 | 1

Notes.

a Includes Turkey, Malaysia and India.

Abbreviations. ASL=arterial spin labeling; EEG= electroencephalogram; MRI=magnetic resonance imaging (structural or functional); NR=not reported; RCT=randomized controlled trial.

### MRI-based Techniques (Structural and Functional MRI, and ASL)

Twelve studies used MRI-based techniques for diagnosis of SUD (k = 3), or prognosis (k = 9) (Table 8). Four used structural MRI,^105,111,115,121^ 7 used fMRI (5 resting and 2 task-specific),^82,104,109,114,116,120,122^, and 1 used MRI, resting fMRI, and ASL.^117^ Six evaluated alcohol use disorder,^82,104,105,109,111,114^ 3 addressed methamphetamine use,^120–122^ and 3 examined cocaine use.^115–117^ Three-quarters evaluated participants in residential or inpatient treatment (k = 8). The most common locations were the US (k = 8) and China (k = 3). All studies were small, with N = 45–188. Seven used machine learning and 5 undertook model validation.

### EEG and Evoked Potentials

Eight studies used EEG data: 6 for diagnosis of SUD^106,108,110,112,118,119^ and 2 for predicting abstinence over a year or more.^107,113^ Most studies addressed alcohol use disorder (k = 6),^106–108,110,112,113^ while the remaining 2 examined opioid use disorder.^118,119^ Four studies used machine learning and 3 undertook model validation.

### Studies in Veteran Populations

Three studies included US Veteran populations and all focused on prognosis and treatment response. One was an RCT including participants with comorbid PTSD and alcohol use disorder,^82^ while the other 2 were cohort studies including both Veteran and civilian populations.^111,122^ One of these also addressed alcohol use disorder^111^ and the other examined methamphetamine use disorder.^122^ All three used structural MRI or fMRI. Two evaluated prediction of relapse^111,122^ and 1 focused on response to psychotherapy.^82^ None validated their predictive models.

## OBSESSIVE COMPULSIVE DISORDER (OCD) AND ANXIETY DISORDERS

### Obsessive Compulsive Disorder

#### Diagnosis

Seventeen studies focused on diagnosis of OCD, with 4 using structural MRI data,^123–126^ 11 using resting fMRI,^127–137^ and 1 each with DTI^138^ and EEG^139^ (Table 9). Eleven used SCID as the diagnostic standard,^123–127,131,134–138^ while 14 studies used the Yale Brown Obsessive Compulsive Scale (Y-BOCS).^123–132,134,135,137,138^ Nearly all studies assessed sensitivity and specificity (k = 14) and evaluated model accuracy (k = 14). Seven studies undertook model validation and 5 used machine learning. All studies had N < 200 and included young adults. Half had 16–40% women participants (k = 9), and 6 included 41–70% women. Most included healthy controls as the comparator (k = 14) and were conducted in China (k = 14).

#### Prognosis & Treatment Response

Only 2 studies evaluated prognosis of OCD; 1 Korean study employed structural MRI to predict response to psychotherapy,^140^ and 1 US study used fMRI to examine response to antidepressants (Table 9).^141^ Both studies used machine learning analyses and validated models. Total study sample sizes were 42 and 131, and both included young adults and substantial proportions of women (38–52%).

Table 9 Characteristics of Included Studies Addressing Obsessive Compulsive Disorder

| Diagnosis (k = 17) | Treatment Response (k = 2)
Neuroimaging/Neurophysiologic technique
Structural MRI | 5 | 1
Functional MRI (fMRI) | 12 | 1
DTI | 1 | ―
EEG | 1 | ―
Other groups included
Healthy controls | 14 | 1
Unmedicated controls | 1 | ―
Country
US | ― | 1
China | 14 | ―
UK/Europe | ― | ―
Other^a^ | 3 | 1
Sample sizes (total N)
30–99 | 7 | 1
100–249 | 9 | 1
Age (mean or median, years)
18–25 | 3 | 1
26–44 | 13 | 1
NR | 1 | ―
% Women
16–40 | 9 | 1
41–70 | 7 | 2
NR | 1 | ―
Race reported? | 1 | ―
Diagnosis/prognosis standards
Clinician interviews | 12 | ―
Clinician assessments | 8 | 1
Patient-reported outcomes | 16 | 1
Study design
Cross-sectional | 16 | ―
Cohort/longitudinal observational | 1 | 2
Analytic approach
Sensitivity/specificity | 15 | ―
Machine learning | 7 | 2
Models validated | 8 | ―

Notes.

a Includes Turkey, Korea, Japan.

Abbreviations. DTI=diffusion tensor imaging; EEG=electroencephalogram; MRI=magnetic resonance imaging; NR=not reported.

### Anxiety Disorders

#### Diagnosis

Four studies addressed diagnosis of anxiety disorders, all using either structural MRI (k = 1)^142^ or fMRI (k = 3; 1 resting and 2 task-specific) (Table 10).^143–145^ All studies used the SCID and/or the Hamilton Anxiety Rating Scale (HAM-A) as the diagnostic standards. Three studies were cross-sectional^142–144^ and 1 was a cohort.^145^ All evaluated the sensitivity, specificity, and accuracy of models, and 3 undertook model validation. Two studies used machine learning. Sample sizes were small (N = 40–93) and included young adults with substantial representation of women.

#### Prognosis and Treatment Response

Six studies evaluated prognosis in anxiety disorders, with 2 using structural MRI^146,147^ and 4 fMRI (all task-specific)^83,148–150^ (Table 10). Specific disorders examined were general anxiety disorder (k = 4),^83,146–148^ social anxiety disorder (k = 1),^149^ and panic disorder (k = 2).^83,150^ Four studies addressed response to psychotherapy,^83,147,149,150^ 1 evaluated outcomes after antidepressant therapy,^146^ and 1 examined response to a computer-based behavioral intervention.^148^ Sample sizes ranged from 34–135, most participants were young adults, and most studies had more than 50% women (k = 5).^83,146,148–150^ Four studies were conducted in the US,^83,147–149^ while the other 2 occurred in Europe.^146,150^ Most studies assessed model accuracy and undertook model validation (k = 5).^146–150^ Two studies used machine learning.^146,150^

Table 10 Characteristics of Included Studies Addressing Anxiety Disorders

| Diagnosis (k = 4) | Treatment Response (k = 6)
Anxiety disorder
Generalized anxiety disorder | 3 | 4
Social anxiety disorder | 1 | 1
Panic disorder | 1 | 2
Neuroimaging/neurophysiologic technique
Structural MRI | 1 | 2
Functional MRI | 3 | 4
Other groups included
Healthy controls | 4 | 1
Unmedicated controls | ― | 1
Country
US | 2 | 4
China | 2 | ―
UK/Europe | ― | 2
Sample sizes (total N)
30–99 | 4 | 5
100–249 | ― | 1
Age (mean or median, years)
18–25 | 2 | 2
26–44 | 1 | 4
NR | 1 | ―
% Women
16–40 | 1 | 1
41–70 | 2 | 3
>70 | 1 | 1
Race reported? | 1 | 2
Diagnosis/prognosis standards
Clinician interviews | 3 | ―
Clinician assessments | 3 | 3
Patient-reported outcomes | 3 | 2
Study design
Cross-sectional | 3 | ―
Cohort/longitudinal observational | 1 | 6
Analytic approach
Sensitivity/specificity | 4 | ―
Machine learning | 2 | 2
Models validated | 2 | 5

Abbreviations. MRI=magnetic resonance imaging; NR=not reported.

## SYSTEMATIC REVIEWS

We identified 30 eligible systematic reviews. Consistent with our findings for primary studies, the majority of reviews addressed depression (k = 17) with fewer evaluating the other conditions: anxiety disorders (k = 3), bipolar disorders (k = 4), PTSD (k = 2), TBI (k = 3), or OCD (k = 1). No eligible review addressed SUD, and none reported on more than 1 condition (Table 11). Most systematic reviews included MRI-based techniques (k = 16) or a number of neuroimaging or neurophysiologic data (k = 7). Fewer focused on EEG (k = 5), PET (k = 1), or SPECT (k = 1).

About half of reviews examined diagnosis (k = 16), 15 addressed response to treatment, and 3 evaluated change in symptoms or functioning. Four reviews reported on both diagnosis and prognosis (Table 11).^151–154^

The number of studies included by reviews varied widely, ranging from 11–352. Eight reviews included less than 20 primary studies, 10 reviews included 20-49, 10 reviews had 50-99, and 2 reviews included ≥100 primary studies. One was an umbrella review that included 24 other systematic reviews, comprising 352 individual primary studies.^155^

Appendix E provides detailed characteristics of eligible systematic review, including condition studied, outcomes reported, and number of studies included.

Table 11 Summary of Eligible Systematic Reviews

| Depression (k = 17) | Bipolar Disorders (k = 4) | PTSD (k = 2) | TBI (k = 3) | OCD (k = 1) | Anxiety Disorders (k = 3)
Diagnosis | 9 | 3 | 1 | 2 | 1 | 2
Prognosis
Response to treatment | 11 | 2 | ― | ― | ― | 1
Change in symptoms or functioning | 1 | ― | 1 | 1 | ― | ―

Abbreviations. OCD=obsessive compulsive disorder; PTSD=posttraumatic stress disorder; TBI=traumatic brain injury.