# METHODS

## TOPIC DEVELOPMENT

We worked with our Operational Partners, the VA SHA305 Working Group, to refine the scope and develop the key questions for this evidence report. To meet the broad scope and main objectives of this workgroup, we conducted an evidence map to identify and describe the current state of research (including evidence gaps) involving the use of a wide variety of neuroimaging and neurophysiologic tests in the context of clinical diagnosis and/or prognosis for a number of important mental health conditions and TBI. An evidence map is also well suited for determining the current state of research areas that have mainly more exploratory or early phase studies. The protocol was developed a priori and registered with Open Science Framework (registration DOI: https://doi.org/10.17605/OSF.IO/5PHG2).

## KEY QUESTION (KQ)

KQ: What are the quantity, distribution, and characteristics of evidence assessing the accuracy and utility of neuroimaging and neurophysiologic biomarkers in the diagnosis and clinical management of the following conditions:

a) Depression
b) Anxiety
c) Posttraumatic stress disorder (PTSD)
d) Substance use disorder (SUD)
e) Bipolar disorder
f) Traumatic brain injury

## SEARCH STRATEGY

We searched for peer-reviewed English language articles from January 2010 to April 2022 in the MEDLINE and Embase databases. We used Medical Subject Headings (MeSH) and title/abstract terms for the neuroimaging and neurophysiological tests, and conditions of interest (Appendix A). We also searched websites for the VA ESP and AHRQ EPC programs for relevant reviews.

## STUDY SELECTION

After duplicates were removed, citations were uploaded into DistillerSR (Evidence Partners, Ottawa, Canada). Abstracts were screened with the assistance of DistillerSR’s Artificial Intelligence System (DAISY) in 2 separate phases. In the first phase, 2 reviewers were required to exclude an abstract at screening (while only 1 reviewer was needed to include for full-text review) until the DAISY-predicted score for likelihood of inclusion was less than 0.4 and the inclusion rate had fallen to less than 5%. Approximately 12,000 abstracts were reviewed in phase 1. In the second phase, for abstracts with DAISY-predicted scores for likelihood of inclusion of 0.2–0.3 (k ≈ 7,000 abstracts), 1 reviewer decided on inclusion for full-text review. The remaining abstracts with DAISY-predicted likelihood scores less than 0.2 were not further reviewed for eligibility (k = 25,912). Based on an inclusion rate of 0.00066 for the last batch of abstracts evaluated during phase 2 (k = 1,526), we conservatively estimate that an additional 17 abstracts may have been potentially included for full-text review, if we had continued with 1-reviewer evaluation of those abstracts with likelihood scores of less than 0.2.

For full-text review, we undertook 2 initial pilot rounds where all reviewers separately determined eligibility for 10–15 articles in each round. We discussed articles to reach consensus on eligibility, with further clarification on operationalization of inclusion and exclusion criteria. Eligibility of remaining articles was determined by 1 reviewer, with ~50% of these also undergoing evaluation by a second reviewer.

Detailed eligibility criteria are provided in Appendix B.

Briefly, eligible populations included adults (≥18 years of age) with at least 1 of the conditions of interest, as noted in KQ above. Eligible articles also evaluated at least 1 neuroimaging or neurophysiological test of interest (eg, magnetic resonance imaging [MRI], including functional MRI [fMRI], diffusion tensor imaging [DTI], positron emission tomography [PET], single photon emission computed tomography [SPECT], and evoked potentials and electroencephalogram [EEG]) for diagnostic accuracy, clinical prognosis, and/or treatment response. Exclusion criteria included pediatric populations, evaluation of mental health symptoms or cognitive functioning only in the context of neurodegenerative conditions (eg, Alzheimer’s dementia or Parkinson’s disease) or intracranial injury (eg, due to ischemic or hemorrhagic stroke). We also excluded studies attempting to evaluate prognostic patterns using exclusively cross-sectional data (eg, comparing current differences in neuroimaging or neurophysiological patterns between patients with depression in remission vs those with treatment-resistant depression). There are very substantial validity concerns with use of cross-sectional data to evaluate predictors of treatment response or general prognosis, which has been noted previously.^22^

## DATA ABSTRACTION

We abstracted the following data from all eligible studies: population characteristics (eg, condition and method of diagnosis, sample size, demographic data (eg, mean or median age, proportion of women, focus on Veterans or combat exposure), neuroimaging test and/or EEG being evaluated (and genetic data if used), outcomes addressed (clinical diagnosis and/or prognosis), and study design (eg, cross-sectional or cohort, analytic methods used to assess diagnostic accuracy). To verify accuracy of abstracted results, data from ~50% of articles were over-read by a second reviewer.

## QUALITY ASSESSMENT AND SUMMARY OF RESULTS

We did not conduct formal quality assessment of eligible studies included in this report. We also did not undertake a formal synthesis of study results. Our results summaries are organized by the conditions of interest and focus on describing the characteristics of study populations, outcomes (clinical diagnosis, prognosis, and/or treatment response), and study designs (including analytic methods) of eligible studies.

## PEER REVIEW

A draft version of this report was reviewed by technical experts as well as clinical leadership. Their comments and our responses are presented in Appendix C.