# INTRODUCTION

Improving diagnosis and treatment outcomes for Veterans with mental health conditions and traumatic brain injury (TBI) continues to be an important priority for the Department of Veterans Affairs (VA). Veterans enrolled in VA healthcare have a high prevalence of these conditions, estimated at 9% for posttraumatic stress disorder (PTSD), 14% for depression, 8% for substance use disorder (SUD), and 5% for anxiety disorders.^1^ Compared with previous service eras, Veterans who served in Iraq and/or Afghanistan have higher rates of PTSD, depression, and/or TBI, due in part to increased diagnosis and the changing nature of military service and combat-related injuries.^2^ These conditions often have substantial impacts on long-term health and functioning for individuals, as well as broader effects on their families and communities.^3–6^ In terms of VA healthcare costs, treatment for mental health conditions accounted for $11 billion or 13% of overall costs in fiscal year 2021 (FY 2021), with estimated annual increases in FY 2022–2024.^7^

In the past several decades, there have been substantial advancements in precision medicine, specifically the use of biomarkers and/or genetics in diagnosis, prognosis, and tailoring treatments for medical conditions. There are currently several ongoing large-scale population-based studies to advance precision medicine, including the VA’s Million Veterans Program.^8,9^ In certain fields, such as oncology, the use of biomarkers and genetics to inform diagnosis and treatment decisions are now the standard of care.^10,11^ However, despite substantial interest in the use of precision medicine techniques in mental health, there has been much more limited progress.^12,13^ In the context of mental health, precision medicine has involved assessment of brain structure and functioning, as well as genetics and serum biomarkers. There are multiple challenges that impact advances in precision medicine for mental health conditions. These include complex and heterogeneous clinical phenotypes, high cost and technical difficulty of obtaining neuroimaging and neurophysiologic data, and differing assessments of symptoms and treatment response.^14–17^ These challenges have contributed to substantial concerns about the reproducibility and validity of findings that rest largely on cross-sectional studies of small samples that insufficiently represent the demographic and clinical variability of affected populations.^15^ Nevertheless, recent efforts to more systematically collect and examine large neuroimaging datasets, including across the lifespan, have yielded more promising results.^15,18^ Thus, future work in this area may yet produce insights that improve diagnosis and treatment outcomes in mental health.

This evidence review was requested by the VA Working Group to implement the Commander John Scott Hannon Veterans Mental Health Care Improvement Act, (P.L. 116-171), Section 305: “Precision Medicine for Veterans Initiative” (SHA305). SHA305 tasks the VA with developing and implementing a precision medicine initiative focused on brain and mental health biomarkers.^19^ SHA305 specifies that this initiative “shall include brain structure and function measurements, such as functional magnetic resonance imaging and electroencephalogram” and further coordinate with current data collection by the Million Veterans Program. To support the VA SHA305 Working Group, we conducted an evidence map to better understand characteristics of existing evidence on relationships between brain structure and functioning, and mental health conditions and TBI. An evidence map is well suited to address a broad scope covering multiple conditions and numerous neuroimaging and neurophysiological techniques, particularly when some of the evidence base may consist of more exploratory studies. An evidence map is also appropriate for meeting the overall goals of informing research policy and potential clinical demonstrations.^20,21^

Therefore, in this report, we provide descriptive information about the number and types of studies that address a wide range of neuroimaging and neurophysiologic assessments for diverse mental health conditions and TBI. We also highlight weaknesses and gaps in the evidence, as determined by the volume and characteristics of studies.