# APPENDIX E ELIGIBLE SYSTEMATIC REVIEWS

Condition | Author, Year | # Included studies | Diagnosis | Prognosis
Condition | Author, Year | # Included studies | Diagnosis | Response to Treatment | Change in Symptoms or Functioning
Depression | Bruun, 2021^349^ | 24 | X
Depression | Cohen, 2021^350^ | 27 | | X
Depression | De Crescenzo, 2017^351^ | 11 | | X
Depression | Dichter, 2015^352^ | 21 | | X
Depression | Enneking, 2020^353^ | 50 | | X
Depression | Fu, 2013^354^ | 20 | | X
Depression | Gillett, 2020^355^ | 21 | | X
Depression | Khosla, 2022^152^ | 132 | X | X
Depression | Levy, 2019^356^ | 19 | | X
Depression | Long, 2020^357^ | 17 | | X
Depression | Masse-Sibille, 2018^358^ | 58 | | X
Depression | Scheepens, 2020^153^ | 14 | X | X
Depression | Siegel-Ramsay, 2022^359^ | 88 | X
Depression | Simon, 2021^360^ | 12 | X
Depression | Sinha, 2020^154^ | 13 | X | | X
Depression | van der Vinne, 2017^361^ | 16 | X
Depression | Widge, 2019^362^ | 76 | X
Bipolar disorders | Hozer, 2016^151^ | 63 | X | X
Bipolar disorders | Librenza-Garcia, 2017^363^ | 51 | X
Bipolar disorders | Seeberg, 2018^364^ | 60 | | X
Bipolar disorders | Whalley, 2012^365^ | 21 | X
PTSD | Colvonen, 2017^366^ | 20 | | X
PTSD | Nelson, 2017^367^ | 37 | | | X
TBI | Haghbayan, 2017^368^ | 58 | | | X
TBI | Hulkower, 2013^369^ | 100 | X
TBI | Raji, 2014^370^ | 71 | X
OCD | Fullana, 2020^155^ | 352^*^ | X
Anxiety disorders | Qing, 2021^371^ | 11 | X
Anxiety disorders | Santos, 2019^372^ | 24 | | X
Anxiety disorders | Xu, 2019^373^ | 29 | X

Notes.

* Umbrella review that identified 24 systematic reviews including 352 primary publications.

Abbreviations. OCD=obsessive compulsive disorder; PTSD=posttraumatic stress disorder; TBI=traumatic brain injury.