# APPENDIX D ELIGIBLE PRIMARY STUDIES

Author, Year | Condition Studied
Author, Year | Depression | Bipolar | Anxiety Disorders | OCD | PTSD | TBI | Substance Use Disorders
Achalia, 2020^163^ | | X
Adinoff, 2015^117^ | | | | | | | X
Almeida, 2013^34^ | X | X
Altuglu, 2020^139^ | | | | X
Ambrosi, 2017^164^ | X | X
Amen, 2017^61^ | X
Amen, 2015^92^ | | | | | X | X
Arns, 2014^165^ | X
Arns, 2012^166^ | X
Arribas, 2010^167^ | | X
Bachmann, 2017^168^ | X
Bailey, 2018^169^ | X
Baranger, 2021^170^ | X
Bares, 2019^171^ | X
Bares, 2017^172^ | X
Bares, 2015^173^ | X
Bartlett, 2018^174^ | X
Baskaran, 2018^175^ | X
Bi, 2019^28^ | X
Bi, 2018^176^ | X
Bi, 2016^31^ | X
Brandt, 2021^177^ | X
Braund, 2022^36^ | X
Brezova, 2014^102^ | | | | | | X
Bruin, 2021^75^ | X | X
Burger, 2017^178^ | X | X
Camchong, 2021^104^ | | | | | | | X
Cash, 2019^179^ | X
Chen, 2022^180^ | X
Chen, 2022^101^ | | | | | | X
Chen, 2021^123^ | | | | X
Chen, 2020^181^ | X
Chen, 2021^182^ | X
Cheng, 2017^183^ | X
Chin Fatt, 2020^184^ | X
Colle, 2015^185^ | X
Cook, 2020^186^ | X
Cook, 2013^54^ | X
Costafreda, 2011^187^ | | X
Crane, 2017^188^ | X
Crowther, 2015^189^ | X
Cui, 2020^137^ | | | | X
Dai, 2021^105^ | | | | | | | X
de la Salle, 2020^190^ | X
Deng, 2018^29^ | X | X
Ding, 2019^48^ | X
Drysdale, 2017^41^ | X
Duan, 2020^191^ | X
Dunlop, 2017^192^ | X
Durazzo, 2017^111^ | | | | | | | X
Ellard, 2018^193^ | X | X
Erguzel, 2020^118^ | | | | | | | X
Erguzel, 2019^119^ | | | | | | | X
Erguzel, 2015^194^ | X
Erguzel, 2014^195^ | X
Etkin, 2019^84^ | | | | | X
Fan, 2022^49^ | X
Fang, 2012^196^ | X
Farb, 2022^197^ | X
Feder, 2017^198^ | X
Fonzo, 2017^85^ | | | | | X
Frangou, 2017^69^ | X | X
Frick, 2020^146^ | | | X
Gao, 2021^199^ | X
Gao, 2022^200^ | X
Gartner, 2018^201^ | X
Ge, 2020^202^ | X
Ge, 2019^203^ | X
Georgopoulos, 2010^91^ | | | | | X
Godlewska, 2018^204^ | X
Godlewska, 2016^205^ | X
Goldstein-Piekarski, 2018^206^ | X
Gong, 2014^207^ | | | | | X
Gong, 2014^208^ | | | | | X
Gong, 2011^209^ | X
Gosnell, 2019^210^ | X
Gowin, 2015^122^ | | | | | | | X
Grieve, 2016^211^ | X
Grotegerd, 2014^212^ | X | X
Guo, 2020^213^ | X
Guo, 2018^214^ | X
Guo, 2012^215^ | X
Guo, 2012^216^ | X
Gyurak, 2016^38^ | X
Hahn, 2015^150^ | | | X
Hahn, 2011^217^ | X
Hanks, 2019^98^ | | | | | | X
Hasanzadeh, 2020^218^ | X
Hasanzadeh, 2019^219^ | X
He, 2019^33^ | X | X
Hellewell, 2019^220^ | X
Hopman, 2021^221^ | X
Hou, 2021^222^ | X
Hou, 2018^223^ | X
Hou, 2018^224^ | X
Hou, 2016^225^ | X
Hu, 2019^226^ | X
Hu, 2019^136^ | | | | X
Hu, 2016^126^ | | | | X
Huang, 2015^99^ | | | | | | X
Ichikawa, 2020^227^ | X
Im, 2017^79^ | | | | | X
Isserles, 2018^51^ | X
James, 2022^90^ | | | | | X
Januszko, 2021^113^ | | | | | | | X
Jaworska, 2018^52^ | X
Jaworska, 2014^228^ | X
Jaworska, 2013^229^ | X
Jiang, 2021^230^ | X
Jiang, 2020^231^ | X
Jiang, 2018^232^ | X
Kamarajan, 2020^106^ | | | | | | | X
Karim, 2018^23^ | X
Kaufman, 2015^59^ | X
Kim, 2020^87^ | | | | | X
Kinreich, 2021^107^ | | | | | | | X
Kipli, 2015^233^ | X
Klumpp, 2020^83^ | X | | X | | X
Klumpp, 2017^149^ | | | X
Koller-Schlaud, 2020^234^ | X
Koo, 2019^235^ | X
Korgaonkar, 2020^37^ | X
Korgaonkar, 2015^236^ | X
Korgaonkar, 2014^237^ | X
Korgaonkar, 2012^32^ | X
Kraus, 2019^238^ | X
Kwak, 2020^132^ | | | | X
Lanka, 2020^76^ | | | | | X
Laxminarayan, 2020^86^ | | | | | X
Leaver, 2018^239^ | X
Lebedeva, 2017^24^ | X
Lee, 2011^240^ | X
Li, 2021^241^ | X
Li, 2021^242^ | X
Li, 2021^243^ | X
Li, 2020^244^ | X
Li, 2020^245^ | | X
Li, 2020^246^ | X
Li, 2019^45^ | X
Li, 2019^121^ | | | | | | | X
Li, 2017^247^ | X | X
Li, 2016^53^ | X
Li, 2014^138^ | | | | X
Li, 2021^248^ | X
Liao, 2018^249^ | X
Liu, 2022^44^ | X
Liu, 2021^127^ | | | | X
Liu, 2021^131^ | | | | X
Liu, 2020^124^ | | | | X
Liu, 2020^250^ | X
Liu, 2020^251^ | X
Liu, 2015^252^ | | | | | X
Liu, 2015^142^ | | | X
Liu, 2014^56^ | X | X
Liu, 2012^253^ | X
Lord, 2012^254^ | X
Lu, 2021^255^ | | X
Lu, 2013^256^ | X
Luo, 2021^130^ | | | | X
Lv, 2021^128^ | | | | X
Main, 2017^100^ | | | | | | X
Manelis, 2020^257^ | X | X
Matsuo, 2019^258^ | X
Matsuoka, 2017^259^ | X
McBride, 2013^103^ | | | | | | X
McHugh, 2014^116^ | | | | | | | X
Meng, 2020^260^ | X
Meyer, 2019^261^ | X
Mishra, 2020^108^ | | | | | | | X
Modinos, 2013^262^ | X
Mohammadi, 2015^263^ | X
Mourao-Miranda, 2012^264^ | X
Mulders, 2020^265^ | X
Mumtaz, 2019^266^ | X
Mumtaz, 2018^267^ | X
Mumtaz, 2018^110^ | | | | | | | X
Mumtaz, 2018^268^ | X
Mumtaz, 2017^269^ | X
Mumtaz, 2017^112^ | | | | | | | X
Mumtaz, 2017^270^ | X
Mwangi, 2016^66^ | | X
Neumeister, 2013^94^ | | | | | X
Nguyen, 2019^271^ | X
Nicholson, 2019^272^ | | | | | X
Niida, 2018^68^ | | X
Niida, 2012^27^ | X | X
Nogovitsyn, 2020^273^ | X
Nord, 2019^274^ | X
Olbrich, 2012^275^ | X
Oliveira-Maia, 2017^276^ | X
Palaniyappan, 2022^277^ | X
Pang, 2020^278^ | X | X
Pantazatos, 2014^145^ | | | X
Patel, 2015^25^ | X
Pillai, 2019^58^ | X
Price, 2018^148^ | | | X
Qiao, 2017^144^ | | | X
Qin, 2022^279^ | X
Qin, 2015^280^ | X
Qin, 2014^281^ | X
Qiu, 2014^282^ | X
Rabinoff, 2011^283^ | X
Raji, 2015^93^ | | | | | X | X
Rangaprakash, 2018^95^ | | | | | X | X
Rangaprakash, 2017^96^ | | | | | X | X
Rangaprakash, 2019^97^ | | | | | X | X
Redlich, 2014^284^ | X | X
Reggente, 2018^141^ | | | | X
Rentzsch, 2014^285^ | X
Richieri, 2018^62^ | X | X
Richieri, 2011^63^ | X | X
Rive, 2016^286^ | X | X
Rocha-Rego, 2014^287^ | | X
Rottstaedt, 2018^288^ | X
Rubin-Falcone, 2018^289^ | X | X
Sacchet, 2015^290^ | X | X
Sadat Shahabi, 2021^291^ | X
Sankar, 2016^292^ | X
Schmaal, 2015^35^ | X
Schnack, 2014^65^ | | X
Schnyer, 2017^30^ | X
Schultz, 2018^293^ | X
Sekutowicz, 2019^109^ | | | | | | | X
Serpa, 2014^71^ | X | X
Shalbaf, 2018^294^ | X
Shan, 2020^295^ | | X
Shan, 2021^296^ | X
Shao, 2019^297^ | X | X
Shi, 2021^298^ | X
Shi, 2018^70^ | X | X
Shim, 2019^47^ | X | | | | X
Shimizu, 2015^299^ | X
Shu, 2014^89^ | | | | | X | X
Siegle, 2012^300^ | X
Squarcina, 2019^301^ | | X
Stange, 2020^302^ | X | X
Stout, 2021^82^ | | | | | X | | X
Stoyanov, 2019^303^ | X
Sun, 2021^304^ | X
Sun, 2022^305^ | X
Sun, 2022^306^ | X | X
Sun, 2020^73^ | X | X
Suo, 2020^78^ | | | | | X
Sverdlov, 2021^307^ | X
Tahmasian, 2017^88^ | | | | | X
Takagi, 2017^135^ | | | | X
Tang, 2022^308^ | X | X
Taylor, 2014^26^ | X
Tekin Erguzel, 2015^64^ | X | X
Tenke, 2011^309^ | X
Tian, 2020^43^ | X
Tsolaki, 2021^72^ | X | X
Uyulan, 2022^310^ | X
van Rooij, 2016^81^ | | | | | X
van Waarde, 2015^311^ | X
Voineskos, 2019^312^ | X
Wade, 2017^313^ | X
Wade, 2016^74^ | X | X
Wade, 2017^314^ | X
Wang, 2022^55^ | X
Wang, 2021^315^ | X
Wang, 2020^316^ | | X
Wang, 2019^133^ | | | | X
Wang, 2019^57^ | X
Wang, 2017^317^ | X
Wang, 2017^318^ | X
Whitfield-Gabrieli, 2016^147^ | | | X
Williams, 2015^39^ | X
Wu, 2020^319^ | X
Wu, 2021^320^ | X
Wu, 2021^46^ | X
Wu, 2017^321^ | | X
Xi, 2022^322^ | X | X
Xiao, 2021^323^ | X
Xing, 2020^143^ | | | X
Xue, 2021^324^ | X
Yan, 2020^325^ | X
Yan, 2022^326^ | X
Yan, 2021^327^ | X
Yan, 2021^120^ | | | | | | | X
Yan, 2021^328^ | X
Yang, 2022^129^ | | | | X
Yang, 2019^134^ | | | | X
Yang, 2018^329^ | X
Yang, 2018^330^ | X
Yang, 2019^331^ | | X
Yang, 2016^332^ | X
Yang, 2021^67^ | X | X
Yeh, 2015^60^ | X
Yoshida, 2017^333^ | X
Yu, 2018^334^ | X
Yun, 2015^140^ | | | | X
Zehong, 2019^50^ | X
Zeng, 2012^335^ | X
Zhai, 2021^115^ | | | | | | | X
Zhang, 2022^336^ | X
Zhang, 2022^337^ | X
Zhang, 2021^42^ | X
Zhang, 2020^77^ | | | | | X
Zhang, 2016^338^ | | | | | X
Zhao, 2020^339^ | X
Zhao, 2017^340^ | X | X
Zhdanov, 2020^341^ | X
Zheng, 2019^342^ | X
Zhong, 2017^343^ | X
Zhou, 2018^125^ | | | | X
Zhu, 2021^344^ | | | | | X
Zhu, 2021^345^ | X
Zhu, 2020^346^ | | | | | X
Zhu, 2018^114^ | | | | | | | X
Zhu, 2018^347^ | X
Zhu, 2019^348^ | X
Zhutovsky, 2019^80^ | | | | | X