# APPENDIX C PEER REVIEW DISPOSITION

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | Thank you.
2 | 2 | Yes | Thank you.
3 | 3 | Yes | Thank you.
4 | 4 | Yes | Thank you.
5 | 5 | Yes | Thank you.
6 | 6 | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence?
7 | 1 | No | Thank you.
8 | 2 | No | Thank you.
9 | 3 | No | Thank you.
10 | 4 | No | Thank you.
11 | 5 | No | Thank you.
12 | 6 | No | Thank you.
Are there any published or unpublished studies that we may have overlooked?
13 | 1 | No | Thank you.
14 | 2 | No | Thank you.
15 | 3 | No | Thank you.
16 | 4 | No | Thank you.
17 | 5 | No | Thank you.
18 | 6 | No | Thank you.
Additional suggestions or comments can be provided below.
19 | 1 | On page 9, the sentence should include the public law number:; This evidence review was requested by the VA Working Group to implement the Commander; John Scott Hannon Veterans Mental Health Care Improvement Act (P.L. 116-171), Section 305: “Precision Medicine for Veterans Initiative” (SHA305). | Thank you, we have updated this in both the evidence summary and main body of the report.
20 | 3 | The authors provide a comprehensive, careful and thoughtful review of studies addressing potential neuroimaging biomarkers for neuropsychiatric conditions. | Thank you.
20 | 3 | This may be in the report, but it is not emphasized: the authors did not assess the various studies for risk of bias since this was not a quantitative review. Therefore, some studies reviewed may provide higher quality data relevant to the questions asked but are treated equally with lower quality studies. I truly don’t think this will change the conclusions, but this is an important caveat that should better highlighted. | We have noted this in both the Methods and Discussion (Limitations) sections. We have also added the need for a future systematic review (that would include formal assessment of studies for risk of bias) to the Discussion.
20 | 3 | Given the impracticality of incorporating MRI into clinical practice (unless effect sizes are large, which they aren’t), would it be worth encouraging more investment on easier-to-implement imaging methods, such as EEG? | We have added additional comment on the potential utility of EEG to the Discussion. There is a much small evidence base on EEG, and it has the same limitations as MRI-based studies. While the apparatus for obtaining EEG is less costly and more portable, it is probably still quite expensive when added on to the clinical assessments that are currently standard care. As we did not directly include evidence on costs (or cost-effectiveness) of these techniques in clinical settings, we do not further differentiate on this basis when discussing Implications for VA policy. Our recommendations for future studies also mainly focus on sample size and better characterization of participants over time; this would require very substantial financial resources even for EEG-based studies.
20 | 3 | I could have missed this, but does fMRI refer only to resting state fMRI, or did some studies attempt to use task fMRI? This would be helpful to highlight and clarify. | We have added information about use of resting and/or task-specific fMRI to the Results.
20 | 3 | On page 14 of the PDF (pg 11 of the report), lines 9-10: I think one of the words “prognosis” should be diagnosis. | We have corrected this.
21 | 6 | I had a comment/question abut the maturity of evidence for implementing MRI for depression diagnosis/prognosis. I have submitted a copy of report with the comment inserted.; Pg 20 Line 42: This statement sounds like there is evidence to implement MRI for depression. Was that the intent?; Pg 49 Lines 43/44: Does this mean the evidence is mature enough to start implementing MRI in the clinic for depression diagnosis and prognosis? | We have revised these statements to make sure we were not implying that the evidence supports using MRI in clinical care for depression. We have also clarified the implications specifically for MRI and EEG in depression care.