# APPENDIX B INCLUSION AND EXCLUSION CRITERIA

| Inclusion Criteria | Exclusion Criteria
Population | N ≥ 30, ≥ 18 years of age or older, with the following conditions:; - Depression; - Anxiety (including OCD, phobias and panic disorders); - Posttraumatic stress disorder (PTSD); - Substance use disorder (SUD); - Bipolar disorder; - Traumatic brain injury (TBI) | - Pediatric populations or mixed pediatric and adult populations without stratified data; - Non-human studies; - Stroke patients (CVA); - Multiple sclerosis; - Intracranial hemorrhage (intracranial etiology, eg, burst aneurysm); - Neurodegenerative conditions (eg, dementia, Parkinson’s disease) except if assessed as outcomes or subsets of eligible conditions
Test of interest | - Magnetic resonance imaging (MRI); - Functional magnetic resonance imaging (fMRI); - Diffusion tensor imagine (DTI); - Perfusion weighted imaging (PWI); - Magnetic resonance spectroscopy (MRS); - Positron emission tomography (PET); - Single photon emission computed tomography (SPECT); - Arterial spin labeling (ASL); - Magnetoencephalography (MEG); - Evoked potentials and electroencephalogram (EEG); - Paired pulse transcranial magnetic stimulation (ppTMS)
Outcomes | Diagnostic accuracy compared with:; - Validated structured clinical interviews (eg, MINI, SCID-5, WHO WMH-CIDI); - Validated clinician reported instruments of symptoms (eg, CAPS, HDRS, HAM-A); - Patient-reported measures of mental health symptoms (eg, PCL-5, PHQ-9, HADS, BDI, GAD-7, AUDIT); - Measures of cognition, other psychiatric symptoms (eg, delusions, hallucinations); Prognosis and treatment response:; - Change in symptoms, cognition, functioning (eg, SF-36, WHODAS); - Sobriety/abstinence or reduction in substance use (SUD only); - Recurrence or relapse (study must define criteria and use validated measures); - Sensitivity (vs lack of response) to treatment; - Self-harm behaviors or suicide risk; - Adverse events and side effects | Only between-group differences (eg, in neuroimaging findings) or cross-sectional correlations with symptom severity
Timing | Published 2010 or later | Earlier than 2010
Setting | Any
Study design | Observational studies, trials, and systematic reviews | Study protocols, case reports, abstracts, editorials; for prognosis and treatment response outcomes, cross-sectional studies